# Acknowledgments

This work was supported by the Intramural Research Program (ES103375, ES103376, ES103377, and ES103380) at the National Institute of Environmental Health Sciences, National Institutes of Health and performed for the National Toxicology Program, Public Health Service, U.S. Department of Health and Human Services under contracts 75N96025C00003, GS-00F-173CA/75N96022F00055, 75N96023A00001, HHSN273201800006C, GS00Q14OADU417 (Order No. HHSN273201600015U), HHSN273201600011C, HHSN273201600020C, HHSN273201500013C, HHSN273201500012C, HHSN273201500006C, HHSN273201400015C, HHSN273201400022C, HHSN273201300009C, HHSN273201300004C, and HHSN316201200054W.