# Appendix G Supplemental Data

Tables with supplemental data can be found here: https://doi.org/10.22427/NTP-DATA-TR-605.

## G.1 Perinatal and Two-year Study (Three-month Interim) – Rats

### G.1.1 Data Tables

I01 - Animal Removal Summary

I02 - Animal Removals

I03 - Growth Curve

I03C - Growth Curve

I04 - Mean Body Weight Summary

I04G - Mean Body Weight Gain

I05 - Clinical Observations Summary

I05D - Detailed Clinical Observations Summary

I05P - Pup Clinical Observations Summary

I05PD - Pup Detailed Clinical Observations Summary

I07 - Mean Water Consumption

I08 - Mean Test Compound Consumption

PA02R - Neoplastic Lesion Summary with Percent and Litter Incidence

PA03R - Nonneoplastic Lesion Summary with Percent and Litter Incidence

PA05R - Incidence Rates of Neoplastic Lesions with Litter Incidence Systemic Lesions Abridged

PA06 - Organ Weights Summary

PA08R - Statistical Analysis of Neoplastic Lesions with Litter Incidence

PA10R - Statistical Analysis of Nonneoplastic Lesions with Litter Incidence

PA14 - Individual Animal Pathology Data

PA18R - Nonneoplastic Lesion Summary with Mean Severity Grade and Litter Incidence

PA41 - Clinical Chemistry Summary

PA43 - Hematology Summary

PA46 - Summary of Gross Pathology

PA48 - Summary of Internal Concentration

R01 - Multigeneration Cross Reference

R02 - Reproductive Performance Summary

R03 - Summary of Litter Data

R04 - Anogenital Distance Summary

R16 - Pubertal Markers Summary

R19 - Pup Mean Body Weight Summary

R19C - Pup Growth Curve

R19G - Pup Mean Body Weight Gain

Vaginal Cytology Markov Model

Vaginal Cytology Plots

Vaginal Cytology Summary

### G.1.2 Individual Animal Data

Individual Animal Body Weight Data

Individual Animal Clinical Chemistry Data

Individual Animal Clinical Observations Data

Individual Animal Consumption Data

Individual Animal Developmental Markers Data

Individual Animal Gross Pathology Data

Individual Animal Hematology Data

Individual Animal Histopathology Slide Review Data

Individual Animal Litter Data

Individual Animal Organ Weight Data

Individual Animal Pup Body Weight Data

Individual Animal Pup Clinical Observations Data

Individual Animal Removal Reasons Data

Individual Animal Reproductive Performance Data

Individual Animal Tissue Concentration Data

## G.2 Perinatal and Two-year Study Tables – Rats

### G.2.1 Data Tables

I01 - Animal Removal Summary

I02 - Animal Removals

I03 - Growth Curve

I03C - Growth Curve

I04 - Mean Body Weight Summary

I04G - Mean Body Weight Gain

I05 - Clinical Observations Summary

I07 - Mean Water Consumption

I08 - Mean Test Compound Consumption

PA02R - Neoplastic Lesion Summary with Percent and Litter Incidence

PA03R - Nonneoplastic Lesion Summary with Percent and Litter Incidence

PA05R - Incidence Rates of Neoplastic Lesions with Litter Incidence Systemic Lesions Abridged

PA08L - Statistical Analysis of Neoplastic Lesions with Litter Incidence

PA10L - Statistical Analysis of Nonneoplastic Lesions with Litter Incidence

PA11 - Statistical Analysis of Survival Data

PA14 - Individual Animal Pathology Data

PA18R - Nonneoplastic Lesion Summary with Mean Severity Grade and Litter Incidence

PA40 - Survival Curve

PA46 - Summary of Gross Pathology

### G.2.2 Individual Animal Data

Individual Animal Body Weight Data

Individual Animal Clinical Observations Data

Individual Animal Consumption Data

Individual Animal DamID and PupID Data

Individual Animal Gross Pathology Data

Individual Animal Histopathology Slide Review Data

Individual Animal Removal Reasons Data

## G.3 Two-year (with Three-month Interim) Study Tables - Mice

### G.3.1 Data Tables

I01 - Animal Removal Summary

I02 - Animal Removals

I03 - Growth Curve

I03C - Growth Curve

I04 - Mean Body Weight Summary

I04G - Mean Body Weight Gain

I05 - Clinical Observations Summary

I07 - Mean Water Consumption

I08 - Mean Test Compound Consumption

PA02 - Neoplastic Lesion Summary with Percent Incidence

PA03 - Nonneoplastic Lesion Summary with Percent Incidence

PA05 - Incidence Rates of Neoplastic Lesions with Systemic Lesions Abridged

PA06 - Organ Weights Summary

PA08 - Statistical Analysis of Neoplastic Lesions

PA08X - Statistical Analysis of Neoplastic Lesions

PA10 - Statistical Analysis of Nonneoplastic Lesions

PA10X - Statistical Analysis of Nonneoplastic Lesions

PA11 - Statistical Analysis of Survival Data

PA14 - Individual Animal Pathology Data

PA18 - Incidence Rates of Nonneoplastic Lesions by Anatomic Site with Average Severity Grade

PA40 - Survival Curve

PA43 - Hematology Summary

PA46 - Summary of Gross Pathology

PA48 - Summary of Internal Concentration

Vaginal Cytology Markov Model

Vaginal Cytology Plots

Vaginal Cytology Summary

### G.3.2 Two-year (with Three-month Interim) Individual Animal Data

Individual Animal Body Weight Data

Individual Animal Clinical Observations Data

Individual Animal Consumption Data

Individual Animal Gross Pathology Data

Individual Animal Hematology Data

Individual Animal Histopathology Data

Individual Animal Organ Weight Data

Individual Animal Removal Reasons Data

Individual Animal Tissue Concentration Data

### G.3.3 Genetic Toxicology

#### G.3.3.1 Genetic Toxicity Evaluation of Sulfolane (126-33-0) in Micronucleus Study in Sprague Dawley Rats

G04 – In Vivo Micronucleus Summary

Individual Animal In Vivo Micronucleus Data

#### G.3.3.2 Genetic Toxicity Evaluation of Sulfolane (126-33-0) in Micronucleus Study in B6C3F1/N Mice

G04 – In Vivo Micronucleus Summary

Individual Animal In Vivo Micronucleus Data