# Appendix F Peer Review Comments

## F.1 Peer Reviewers

External peer review of the draft NTP Technical Report on the Toxicology and Carcinogenesis Studies of Sulfolane (CASRN 126-33-0) Administered in Drinking Water to Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) Rats and B6C3F1/N Mice was conducted by four subject matter experts who individually provided comments via letter. Individuals outside the federal government were invited to serve as peer reviewers because of their expertise and then vetted, following established National Toxicology Program (NTP) practices, to ensure no conflicts of interest. For peer review of this draft NTP report, the peer reviewers had expertise in chemical toxicology, in-vitro biology, pharmacology, regulatory toxicology, reproductive toxicology, toxicologic pathology, and vascular carcinogenicity.

The peer reviewers were charged to peer review the draft NTP report and provide recommended revisions that would strengthen the scientific analyses or conclusions.

The report preparation team carefully considered the peer reviewers’ comments in revising the report. The peer reviewers’ anonymized comments, presented in random order, are provided verbatim in this appendix, other than for the correction of minor grammatical or typographical errors.

Reviewers:

- Charles A. Easley, Ph.D.
  Associate Professor, Department of Environmental Health Science
  University of Georgia
  Athens, Georgia, USA
- Elana R. Elkin, Ph.D., M.P.H.
  Assistant Professor, Division of Environmental Health
  San Diego State University
  San Diego, California, USA
- Debie J. Hoivik, Ph.D.
  Vice President, Early Development
  Akebia Therapeutics
  Cambridge, Massachusetts, USA
- Kevin A. Keane, D.V.M., Ph.D.
  Senior Director of Pathology
  Blueprint Medicines
  Cambridge, Massachusetts, USA

## F.2 Peer Review Charge and Instructions

Charge:

Peer review the draft NTP Technical Report on the Toxicology and Carcinogenesis Studies of Sulfolane (CASRN 126-33-0) Administered in Drinking Water to Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) Rats and B6C3F1/N Mice.

Instructions:

For the numbered charge questions, provide any recommended revisions necessary for strengthening the scientific analyses or conclusions of the draft NTP Technical Report. As available, please provide the page and line number(s), table number, and/or figure number to which the specific comments refer.

## F.3 Peer Review Comments

### F.3.1 Reviewer 1

1. Information presentation:

a. Please comment on whether the information presented in the draft NTP Technical Report, including presentation of data in any tables and figures, is technically correct, clearly stated, and objectively presented.
  - Reviewer Comments: The Technical Report is very well-written. The data are clearly stated, the methodologies are well-described and detailed, the statistical tests are very detailed and well-justified, and the overall presentation of the data is excellent. I particularly like the background provided and the commentary on the current literature.
b. Please suggest any improvements to the information presented and provide your rationale or scientific support for proposed improvements where applicable.
  - Reviewer Comments: I recommend adding more details on why the doses were chosen especially since they differ from the 28-day report and are substantially higher than levels reported in well water in Alaska.
    - Especially with the rat studies, a number of animals died during the 2-year study, I recommend the authors comment on that in more detail and discuss whether these death rates are common in the historical studies. I imagine that they are, but I believe that adding more information will provide better context. Considering that the number of animals that died was higher in the 1000 mg/L dose, it might be difficult to say that there isn’t a sulfolane-mediated effect.
    - The 28-day study observed a number of non-neoplastic lesions, it appears these weren’t observed in the 2-year study in the same strain of rats, can the authors add more information as to why they did not see the same lesions in this Report?
    - Especially in the rat studies, can the authors comment more about whether intake by males being less than females impacted the overall results (specifically in the section on page 43)?
    - For the mice studies, do female animals retain more sulfolane or more slowly metabolize it compared to males? If so, can the authors add more detail into how that might impact the results?
    - The follicular cyst data in mice are really interesting, the authors mention that the toxicological significance of this finding is unknown, but I would recommend expanding on this notion. This knowledge could be useful for physicians in regions with potential exposure to sulfolane to treat their patients, especially if there is a potential impact on fertility long-term.
    - In two different places in the Discussion section, the authors comment: “It is possible the difference in findings was due to sensitivity differences between rat stocks” when discussing previously published results, but other previous studies, including the 28-day Technical Report suggest that there is not species sensitivity to sulfolane. I would recommend editing these statements or proposing more precise explanations for why there are differences in this study. The Technical Report here is incredibly rigorous, so the presented data is likely more accurate.
c. Please identify any information that should be added or deleted and provide your rationale behind the additions or deletions.
  - Reviewer Comments: In Appendix D, I would either include Tables 12 and 21 in this section or at least reference them in the Appendix.
    - On page 7, there is the following error: Table A 1Error! Reference source not found. Please add back the reference source
    - In the “Preparation and Analysis of Dose Formulations,” only one dose appears to be tested for stability. What is the rationale for this? Why just the lowest dose vs the highest dose?
    - In this same section, the authors importantly note differences in target concentrations. Did these differences affect the results in any way? Presumably not, but the authors should add a statement addressing whether this impacted the results or not.
    - While the authors note that sperm counts were not assessed due to sample clumping, were any histology assessments conducted on testis tissue? If so, discussing those results (even if there were no changes in seminiferous tubule morphology, etc.) would give more credence to the idea that the concentrations tested did not impact male fertility
    - In Table 11, were the Chemical Intake Calculations validated by internal plasma concentration values per animal?
    - In the Conclusion section, I recommend adding the follicular cyst data.

2. Study design, conduct, and findings:

a. Please comment on the adequacy of the experimental design and methods used for execution of the studies. Provide your rationale or scientific support for proposed changes where the approach is deemed insufficient.
  - Reviewer Comments: The experimental design and methods are rigorous and robust and give lots of credence to the results. This is a very well-designed, well-executed study with meaningful results.
b. Please comment on whether the statistical analyses have been appropriately applied and scientifically justified. Provide your rationale or scientific support for any proposed changes to the statistical analyses.
  - Reviewer Comments: The statistical tests and analyses are very well described, are detailed well, and are easily justified. My only recommendation is that in the methods, significance is less than 0.05, but in some of the tables and graphs, significance less than 0.01 is noted. I would include this in the methodology section as well.
c. Please comment on whether the scientific interpretations of the data are objectively presented and scientifically justified. Please specify any study conclusions that are not justified and provide alternate interpretation of the data.
  - Reviewer Comments: All the interpretations of the data are justified and scientifically sound. I have no objections as to how the data were interpreted.

3. Levels of Evidence of Carcinogenic Activity categories:

Information on the NTP Levels of Evidence of Carcinogenic Activity is available at https://ntp.niehs.nih.gov/sites/default/files/ntp/test_info/cartox_loe_508.pdf and in the draft NTP Technical Report.

a. Indicate your agreement or disagreement with each draft NTP Level of Evidence conclusion, taking into consideration the strength of the toxicology and carcinogenicity results in Hsd:Sprague Dawley SD rats and B6C3F1/N mice exposed to sulfolane:
  - Male Hsd:Sprague Dawley SD rats:
    - No evidence of carcinogenic activity
      - ☒ Agree
        ☐ Agree in principle with the exceptions listed below:
        ☐ Do not agree with interpretations because:
  - Female Hsd:Sprague Dawley SD rats:
    - Equivocal evidence of carcinogenic activity
      - Increased incidence of mammary gland adenoma
        ☒ Agree
        ☐ Agree in principle with the exceptions listed below:
        ☐ Do not agree with interpretations because:
  - Male B6C3F1/N mice:
    - Clear evidence of carcinogenic activity
      - Increased incidence of hemangiosarcoma (all organs), predominantly occurring in the liver
        ☒ Agree
        ☐ Agree in principle with the exceptions listed below:
        ☐ Do not agree with interpretations because:
  - Female B6C3F1/N mice:
    - Equivocal evidence of carcinogenic activity
      - Increased incidence of hepatocellular carcinoma
        ☒ Agree
        ☐ Agree in principle with the exceptions listed below:
        ☐ Do not agree with interpretations because:

4. Please provide any additional comments, suggestions, or recommendations for improving the report and provide rationale or scientific support for proposed improvements where applicable.

- Reviewer Comments: At the end of the Discussion section, the authors write: “Previously, a chronic reference dose of 10 µg/kg/day was calculated, which was based on the finding of reduced leukocytes within female rats following a 90-day drinking water exposure^27^ and for which a drinking water screening level of 365 ppb was derived.^83^ The data presented here may influence these values.” I would consider re-wording this statement because it might lead policymakers to assume that higher levels of sulfolane in drinking water are safe.
  - The authors accurately state that hemangiosarcomas are more prevalent in mice compared to rats and humans, and as presented, this statement draws concerns about the mouse model for these types of studies. I would add additional text to highlight the limitations (as they have done) but also talk about the strengths and how the observed data still indicate clear evidence for carcinogenicity.

### F.3.2 Reviewer 2

1. Information presentation:

a. Please comment on whether the information presented in the draft NTP Technical Report, including presentation of data in any tables and figures, is technically correct, clearly stated, and objectively presented.
  - Reviewer Comments: I have no issues with the presentation of the data. No changes proposed.
b. Please suggest any improvements to the information presented and provide your rationale or scientific support for proposed improvements where applicable.
  - Reviewer Comments: See my comments in part 1C.
c. Please identify any information that should be added or deleted and provide your rationale behind the additions or deletions.
  - Reviewer Comments: The section titled “Exposure Concentration Selection Rationale” gives a brief rationale for the doses used in the rat and mice experiments outlined in the technical report. This section is very important. In the early years of toxicology studies, very high doses of toxicants were given to animals with little regard to the relevance of probable human exposures levels. Now, that idea has drastically changed. Human relevance and justification of the doses is one of the most important aspects of the study for translatability and extrapolation. Although the study gives some justification for doses, I believe they are inadequate. Many sentences in the paragraph refer the reader to other sources/references that the reader must look up on their own to further understand the dosing justifications. Because of the importance of dosing justification in the context of acceptable toxicology studies done in this field today, these justifications should be more explicitly stated and cited properly so that the reader does not have to do more work to understand the justification for doses. I think this section needs to be reviewed by the authors carefully and make sure they are making it as easy for the reader as possible to understand why they are using doses as high as 1000 mg/L. Page 8 line 38-39 and page 9 line 1-6.

2. Study design, conduct, and findings:

a. Please comment on the adequacy of the experimental design and methods used for execution of the studies. Provide your rationale or scientific support for proposed changes where the approach is deemed insufficient.
  - Reviewer Comments:
    - What is the rationale for using “teflon-lined” lids to seal the sulfolane dose preparations? There would a slight concern for PFAS-family chemical contamination depending on what chemicals were used to manufacture the “teflon-lined” lids and whether there is any risk of sulfolane touching/mixing with “teflon-lined.” If this specific lid serves a specific purpose, I would suggest stating that purpose (ie to prevent evaporation etc.). Otherwise, it seems like a pointless fact to add to the methods. Page 8, Lines 5-6.
    - Why were more female F1 rats held in a single cage compared to males? Again may want to explain why. Page 10, Line 16.
b. Please comment on whether the statistical analyses have been appropriately applied and scientifically justified. Provide your rationale or scientific support for any proposed changes to the statistical analyses.
  - Reviewer Comments: No changes proposed.
c. Please comment on whether the scientific interpretations of the data are objectively presented and scientifically justified. Please specify any study conclusions that are not justified and provide alternate interpretation of the data.
  - Reviewer Comments: Please see my level of evidence comments.

3. Levels of Evidence of Carcinogenic Activity categories:

Information on the NTP Levels of Evidence of Carcinogenic Activity is available at https://ntp.niehs.nih.gov/sites/default/files/ntp/test_info/cartox_loe_508.pdf and in the draft NTP Technical Report.

a. Indicate your agreement or disagreement with each draft NTP Level of Evidence conclusion, taking into consideration the strength of the toxicology and carcinogenicity results in Hsd:Sprague Dawley SD rats and B6C3F1/N mice exposed to sulfolane:
  - Male Hsd:Sprague Dawley SD rats:
    - No evidence of carcinogenic activity
      - ☒ Agree
        ☐ Agree in principle with the exceptions listed below:
        ☐ Do not agree with interpretations because:
  - Female Hsd:Sprague Dawley SD rats:
    - Equivocal evidence of carcinogenic activity
      - Increased incidence of mammary gland adenoma
        ☐ Agree
        ☐ Agree in principle with the exceptions listed below:
        ☒ Do not agree with interpretations because:
        - I don’t believe there is enough evidence to make the overall conclusion of equivocal evidence of carcinogenic activity based only “increased incidence” of mammary gland adenoma in one treatment group. In Table 17, it shows only one dose, the middle dose of 100 mg/L increasing the incidence over the other treatment groups with a p-value 0.036. Although this p-value is technically significant based on a p<0.05 definition, it is still not particularly convincing. Looking at the full context of the results for the female rats, there was no dose-response relationship, only one group showing higher incidence in one type of tumor out of two listed. I don’t think this evidence rises to the level of any carcinogenic activity. I would change this conclusion to no evidence of carcinogenic activity.
  - Male B6C3F1/N mice:
    - Clear evidence of carcinogenic activity
      - Increased incidence of hemangiosarcoma (all organs), predominantly occurring in the liver
        ☒ Agree
        ☐ Agree in principle with the exceptions listed below:
        ☒ Do not agree with interpretations because:
        - I agree that the data at the 1000 mg/L are consistent with increased incidence of carcinogenesis, however, the concentration is so high that I’m not sure how relevant is it to actual human exposures.
  - Female B6C3F1/N mice:
    - Equivocal evidence of carcinogenic activity
      - Increased incidence of hepatocellular carcinoma
        ☒ Agree
        ☐ Agree in principle with the exceptions listed below:
        ☐ Do not agree with interpretations because:

4. Please provide any additional comments, suggestions, or recommendations for improving the report and provide rationale or scientific support for proposed improvements where applicable.

- Reviewer Comments: [No comments]

### F.3.3 Reviewer 3

1. Information presentation:

a. Please comment on whether the information presented in the draft NTP Technical Report, including presentation of data in any tables and figures, is technically correct, clearly stated, and objectively presented.
  - Reviewer Comments: The integrated and summarized word document was presented in a standard and easily understood format (e.g., intro, M&M, results, etc.). The pertinent tables were expertly prepared and inserted into this document and this made it quite easy to review. Additionally, the folders with background reports were useful. There was a minor issue in getting the individual data tables (due to some PDF watermarking format) but this was readily resolved by the NTP staff, and these data were subsequently received in a timely manner.
b. Please suggest any improvements to the information presented and provide your rationale or scientific support for proposed improvements where applicable.
  - Reviewer Comments: It would be ideal if there could be links in the integrated document [that] could take one to the ancillary file (e.g. individual data) of interest rather than the reviewer having to hunt for this document in the review packet. The vast number of files associated with this technical report makes searching for an individual data file a cumbersome process.
c. Please identify any information that should be added or deleted and provide your rationale behind the additions or deletions.
  - Reviewer Comments: Given that there were minor findings in the associated immunotoxicity studies (e.g., reduced NK cells), it could be more clearly stated if there were any non-neoplastic immune tissue findings that were observed that maybe associated with the neoplastic findings, especially in the same tissues as those identified below.

2. Study design, conduct, and findings:

a. Please comment on the adequacy of the experimental design and methods used for execution of the studies. Provide your rationale or scientific support for proposed changes where the approach is deemed insufficient.
  - Reviewer Comments: The unusual study design which includes gestational exposure may be something that warrants further discussion and justification. I am not inherently opposed to this study design but consider that a non-neoplastic developmental issue may skew the results of the assessment of neoplasia. I admit that I did not find any evidence even with careful review of the developmental data provided. Thus, I admit this concern is more hypothetical than real based on the data herein.
b. Please comment on whether the statistical analyses have been appropriately applied and scientifically justified. Provide your rationale or scientific support for any proposed changes to the statistical analyses.
  - Reviewer Comments: The statistical analyses were complete and appropriately applied.
c. Please comment on whether the scientific interpretations of the data are objectively presented and scientifically justified. Please specify any study conclusions that are not justified and provide alternate interpretation of the data.
  - Reviewer Comments: I believe your conclusions below are conservative (albeit justified) in the two cases below for the reasons stated.

3. Levels of Evidence of Carcinogenic Activity categories:

Information on the NTP Levels of Evidence of Carcinogenic Activity is available at https://ntp.niehs.nih.gov/sites/default/files/ntp/test_info/cartox_loe_508.pdf and in the draft NTP Technical Report.

a. Indicate your agreement or disagreement with each draft NTP Level of Evidence conclusion, taking into consideration the strength of the toxicology and carcinogenicity results in Hsd:Sprague Dawley SD rats and B6C3F1/N mice exposed to sulfolane:
  - Male Hsd:Sprague Dawley SD rats:
    - No evidence of carcinogenic activity
      - ☒ Agree
        ☐ Agree in principle with the exceptions listed below:
        ☐ Do not agree with interpretations because:
  - Female Hsd:Sprague Dawley SD rats:
    - Equivocal evidence of carcinogenic activity
      - Increased incidence of mammary gland adenoma
        ☐ Agree
        ☒ Agree in principle with the exceptions listed below:
        - The non-dose response of this common finding (presence in the 100 mg/L group) gives considerable concern that this is a spurious background finding.
        ☐ Do not agree with interpretations because:
  - Male B6C3F1/N mice:
    - Clear evidence of carcinogenic activity
      - Increased incidence of hemangiosarcoma (all organs), predominantly occurring in the liver
        ☒ Agree
        ☐ Agree in principle with the exceptions listed below:
        ☐ Do not agree with interpretations because:
  - Female B6C3F1/N mice:
    - Equivocal evidence of carcinogenic activity
      - Increased incidence of hepatocellular carcinoma
        ☐ Agree
        ☒ Agree in principle with the exceptions listed below:
        - The high incidence of these findings in the control group (combined 11/50 or 22%) gives concern that this is a spurious background finding in all dose groups.
        ☐ Do not agree with interpretations because:

4. Please provide any additional comments, suggestions, or recommendations for improving the report and provide rationale or scientific support for proposed improvements where applicable.

- Reviewer Comments: Accessing the report in the ECB system is quite cumbersome. It is far easier to work in the Kiteworks system.

### F.3.4 Reviewer 4

1. Information presentation:

a. Please comment on whether the information presented in the draft NTP Technical Report, including presentation of data in any tables and figures, is technically correct, clearly stated, and objectively presented.
  - Reviewer Comments: Information was clearly presented.
b. Please suggest any improvements to the information presented and provide your rationale or scientific support for proposed improvements where applicable.
  - Reviewer Comments: None
c. Please identify any information that should be added or deleted and provide your rationale behind the additions or deletions.
  - Reviewer Comments: None

2. Study design, conduct, and findings:

a. Please comment on the adequacy of the experimental design and methods used for execution of the studies. Provide your rationale or scientific support for proposed changes where the approach is deemed insufficient.
  - Reviewer Comments: Experimental design adequate.
b. Please comment on whether the statistical analyses have been appropriately applied and scientifically justified. Provide your rationale or scientific support for any proposed changes to the statistical analyses.
  - Reviewer Comments: No comment
c. Please comment on whether the scientific interpretations of the data are objectively presented and scientifically justified. Please specify any study conclusions that are not justified and provide alternate interpretation of the data.
  - Reviewer Comments: Data is presented in a balanced, objective manner.

3. Levels of Evidence of Carcinogenic Activity categories:

Information on the NTP Levels of Evidence of Carcinogenic Activity is available at https://ntp.niehs.nih.gov/sites/default/files/ntp/test_info/cartox_loe_508.pdf and in the draft NTP Technical Report.

a. Indicate your agreement or disagreement with each draft NTP Level of Evidence conclusion, taking into consideration the strength of the toxicology and carcinogenicity results in Hsd:Sprague Dawley SD rats and B6C3F1/N mice exposed to sulfolane:
  - Male Hsd:Sprague Dawley SD rats:
    - No evidence of carcinogenic activity
      - ☒ Agree
        ☐ Agree in principle with the exceptions listed below:
        ☐ Do not agree with interpretations because:
  - Female Hsd:Sprague Dawley SD rats:
    - Equivocal evidence of carcinogenic activity
      - Increased incidence of mammary gland adenoma
        ☒ Agree
        ☐ Agree in principle with the exceptions listed below:
        ☐ Do not agree with interpretations because:
  - Male B6C3F1/N mice:
    - Clear evidence of carcinogenic activity
      - Increased incidence of hemangiosarcoma (all organs), predominantly occurring in the liver
        ☒ Agree
        ☐ Agree in principle with the exceptions listed below:
        ☐ Do not agree with interpretations because:
  - Female B6C3F1/N mice:
    - Equivocal evidence of carcinogenic activity
      - Increased incidence of hepatocellular carcinoma
        ☒ Agree
        ☐ Agree in principle with the exceptions listed below:
        ☐ Do not agree with interpretations because:

4. Please provide any additional comments, suggestions, or recommendations for improving the report and provide rationale or scientific support for proposed improvements where applicable.

- Reviewer Comments: Studies and report are well done.