# Appendix E Genetic Toxicology

## E.1 Evaluation Protocol

National Toxicology Program (NTP) reports consider biological as well as statistical factors to determine an overall assay result. For an individual assay, the statistical procedures for data analysis are described in the following protocols. There have been instances, however, in which multiple samples of a chemical were tested in the same assay, and different results were obtained among these samples and/or among laboratories. In such cases, all the data are critically evaluated with attention given to possible protocol variations in determining the weight of evidence for an overall conclusion of chemical activity in an assay. The summary table in the abstract of this technical report presents the Division of Translational Toxicology’s (DTT’s) scientific judgment regarding the overall evidence for activity of the chemical in an assay.

## E.2 Micronucleus Assay

### E.2.1 Peripheral Blood Micronucleus Test Protocol

Peripheral blood samples were analyzed by Integrated Laboratory Systems, LLC (ILS; Research Triangle Park, NC) for determination of erythrocyte micronucleus frequencies. At the 3-month interim evaluation of sulfolane, blood samples (approximately 200 μL) were collected from male and female rats and mice, placed in tripotassium ethylenediaminetetraacetic acid (K_3_ EDTA)-coated tubes, and shipped overnight to the testing laboratory. Upon arrival, blood samples were fixed in ultracold methanol using a MicroFlowPLUS Kit (Litron Laboratories, Rochester, NY) according to the manufacturer’s instructions. Fixed samples were stored in a −80°C freezer until analysis. Thawed blood samples were analyzed for frequency of micronucleated immature erythrocytes (i.e., reticulocytes or polychromatic erythrocytes [PCEs]) and mature erythrocytes (i.e., normochromatic erythrocytes [NCEs]) using a flow cytometer^86^; both the mature and immature erythrocyte populations can be analyzed separately by employing special cell surface markers to differentiate the two cell types. Because the very young reticulocyte subpopulation (CD71+ cells) can be targeted using this technique, rat blood samples can be analyzed for damage that occurred in the bone marrow within the past 24–48 hours, before the rat spleen appreciably alters the percentage of reticulocytes in circulation.^87^ In mice, both the mature and immature erythrocyte populations can be evaluated for micronucleus frequency because the mouse spleen does not sequester and eliminate damaged erythrocytes. Damaged erythrocytes achieve steady state in the peripheral blood of mice after 4 weeks of continuous exposure. Approximately 20,000 reticulocytes and 1 × 10^6^ erythrocytes were analyzed per animal for frequency of micronucleated cells, and the percentage of immature erythrocytes (% PCE) was calculated as a measure of bone marrow toxicity resulting from chemical exposure.

Prior experience with the large number of cells scored using flow cytometric scoring techniques^88^ suggests it is reasonable to assume that the proportion of micronucleated reticulocytes is approximately normally distributed. The statistical tests selected for trend and for pairwise comparisons with the control group depend on whether the variances among the groups are equal. The Levene test at α = 0.05 is used to test for equal variances. In the case of equal variances, linear regression is used to test for a linear trend with exposure concentration, and the Williams test is used to test for pairwise differences between each exposed group and the control group. In the case of unequal variances, the Jonckheere test is used to test for linear trend, and the Dunn test is used for pairwise comparisons of each exposed group with the control group. To correct for multiple pairwise comparisons, the p value for each comparison with the control group is multiplied by the number of comparisons made. In the event that this product is >1.00, it is replaced with 1.00. Trend tests and pairwise comparisons with the control group are considered statistically significant at p ≤ 0.025.

In the micronucleus test, it is preferable to base a positive result on the presence of both a positive trend as well as at least one significantly elevated exposed group compared with the corresponding control group. In addition, historical control data are used to evaluate the biological significance of any observed response. Both statistical significance and biological significance are considered when arriving at a call. The presence of either a positive trend or a single significant exposed group generally results in an equivocal call. The absence of both a trend and any significant differences between exposed groups and the control group results in a negative call. Ultimately, the scientific staff determines the final call after considering the results of statistical analyses, reproducibility of any effects observed (in acute studies), and the magnitudes of those effects.

### E.2.2 Results

The genetic toxicity of sulfolane was evaluated in the peripheral blood micronucleus tests in rats and mice after exposure to sulfolane via drinking water. Micronucleated reticulocytes were not increased in male and female rats exposed to sulfolane for 3 months via drinking water (0, 30, 100, 300, 1,000 mg/L) (Table E-1), and there were no increases in micronucleated reticulocytes and micronucleated erythrocytes in male and female mice exposed to sulfolane for 3 months via drinking water (0, 30, 100, 300, 1,000 mg/L) (Table E-2). A positive trend in the percentage of reticulocytes was observed for female rats in the 3-month study, but the increase was within the historical 95% confidence interval. Data from all NTP genetic toxicity tests with sulfolane are available in the NTP Chemical Effects in Biological Systems database: https://doi.org/10.22427/NTP-DATA-TR-605.^79^

Table E-1 Frequency of Micronuclei in Peripheral Blood Erythrocytes of Male and Female Rats in the Three-month Interim Evaluation during the Perinatal and Two-year Drinking Water Study of Sulfolane

| Number of Rats with Erythrocytes Scored | Micronucleated PCEs/1,000 PCEs^a^ | P Value^b^ | Micronucleated NCEs/1,000 NCEs^a^ | P Value^b^ | PCEs (%)^a^ | P Value^b^
Male
Exposure Concentration (mg/L)
0 | 6 | 0.783 ± 0.139 | | 0.164 ± 0.028 | | 1.214 ± 0.177
30 | 5 | 0.850 ± 0.208 | 0.6413 | 0.124 ± 0.043 | 0.7729 | 1.128 ± 0.105 | 0.7672
100 | 5 | 0.677 ± 0.122 | 0.7334 | 0.101 ± 0.014 | 0.8536 | 1.077 ± 0.053 | 0.8860
300 | 5 | 0.640 ± 0.080 | 0.7713 | 0.161 ± 0.035 | 0.8830 | 1.176 ± 0.075 | 0.9251
1,000 | 5 | 0.600 ± 0.091 | 0.7920 | 0.098 ± 0.030 | 0.8975 | 1.145 ± 0.076 | 0.9432
Trend^c^ | | p = 0.8790 | | p = 0.8350 | | p = 0.9011
Female
Exposure Concentration (mg/L)
0 | 5 | 0.580 ± 0.132 | | 0.080 ± 0.023 | | 1.156 ± 0.082
30 | 5 | 0.760 ± 0.116 | 0.4516 | 0.109 ± 0.031 | 0.2964 | 1.041 ± 0.129 | 1.0000
100 | 5 | 0.530 ± 0.098 | 0.5318 | 0.090 ± 0.023 | 0.3542 | 1.206 ± 0.036 | 1.0000
300 | 5 | 0.540 ± 0.073 | 0.5647 | 0.141 ± 0.029 | 0.2756 | 1.289 ± 0.139 | 1.0000
1,000 | 5 | 0.560 ± 0.081 | 0.5820 | 0.077 ± 0.015 | 0.2867 | 1.511 ± 0.142 | 0.2347
Trend | | p = 0.7247 | | p = 0.6948 | | p = 0.0191

PCE = polychromatic erythrocyte (i.e., reticulocyte); NCE = normochromatic erythrocyte (i.e., mature erythrocyte).

^a^ Data are presented as mean ± standard error.

^b^ Pairwise comparisons with the vehicle control group performed using the Williams or Dunn test (p ≤ 0.025).

^c^ Exposure-related trends evaluated by linear regression or the Jonckheere test (p ≤ 0.025).

Table E-2 Frequency of Micronuclei in Peripheral Blood Erythrocytes of Male and Female Mice in the Three-month Interim Evaluation during the Two-year Drinking Water Study of Sulfolane

| Number of Mice with Erythrocytes Scored | Micronucleated PCEs/1,000 PCEs^a^ | P Value^b^ | Micronucleated NCEs/1,000 NCEs^a^ | P Value^b^ | PCEs (%)^a^ | P Value^b^
Male
Exposure Concentration (mg/L)
0 | 5 | 2.630 ± 0.203 | | 1.544 ± 0.025 | | 1.538 ± 0.079
30 | 5 | 2.600 ± 0.156 | 0.5209 | 1.585 ± 0.052 | 0.4767 | 1.513 ± 0.092 | 1.0000
100 | 5 | 2.670 ± 0.143 | 0.5230 | 1.510 ± 0.042 | 0.5592 | 1.516 ± 0.063 | 1.0000
300 | 5 | 2.920 ± 0.241 | 0.3417 | 1.581 ± 0.028 | 0.5040 | 1.585 ± 0.096 | 0.8652
1,000 | 5 | 2.700 ± 0.239 | 0.3535 | 1.537 ± 0.051 | 0.5213 | 1.611 ± 0.053 | 0.6563
Trend^c^ | | p = 0.3697 | | p = 0.6003 | | p = 0.2922
Female
Exposure Concentration (mg/L)
0 | 5 | 2.870 ± 0.244 | | 1.383 ± 0.302 | | 1.960 ± 0.379
30 | 5 | 2.060 ± 0.206 | 0.9866 | 1.006 ± 0.020 | 1.0000 | 1.798 ± 0.220 | 1.0000
100 | 5 | 2.020 ± 0.101 | 0.9960 | 0.978 ± 0.039 | 1.0000 | 1.799 ± 0.107 | 1.0000
300 | 5 | 2.400 ± 0.174 | 0.9975 | 1.077 ± 0.054 | 1.0000 | 1.830 ± 0.104 | 1.0000
1,000 | 5 | 2.020 ± 0.115 | 0.9984 | 1.007 ± 0.043 | 1.0000 | 1.794 ± 0.128 | 1.0000
Trend | | p = 0.9091 | | p = 0.8642 | | p = 0.9238

PCE = polychromatic erythrocyte (i.e., reticulocyte); NCE = normochromatic erythrocyte (i.e., mature erythrocyte).

^a^ Data are presented as mean ± standard error.

^b^ Pairwise comparisons with the vehicle control group performed using the Williams or Dunn test (p ≤ 0.025).

^c^ Exposure-related trends evaluated by linear regression or the Jonckheere test (p ≤ 0.025).