# Appendix D Sulfolane Concentration Determination

## D.1 Sample Collection

At the 3-month interim evaluation, five F_1_ rats/sex/exposure group and five mice/sex/exposure group were anesthetized with a CO_2_/O_2_ mixture, and blood was collected from the retroorbital plexus (rats) or by cardiac puncture (mice). The blood samples were collected within 2 hours after lights were turned on (approximately 6 a.m.), placed into tubes containing tripotassium ethylenediaminetetraacetic acid (K_3_ EDTA), and centrifuged to separate the plasma. Plasma samples were frozen at approximately −70°C and shipped to the analytical laboratory (RTI International, Research Triangle Park, NC).

## D.2 Sample Analysis

Sulfolane concentrations in samples were quantified using validated analytical methods.^39^ Briefly, a 100 µL aliquot of plasma was transferred to a screw-cap microcentrifuge tube, and 10 µL of deionized water was added and mixed. To each sample, 10 µL of internal standard solution (2 µg/mL sulfolane-d8) and a 50 µL aliquot of 1 N NaOH solution were added and briefly mixed. A 500 µL aliquot of ethyl acetate was added and mixed by vortex for 5 minutes. The extracts were centrifuged for 5 minutes at 14,000 rpm at 4°C. To each supernatant, 50 µL of isopropanol was added, and the volume was reduced to 50 µL under nitrogen at room temperature. The concentrated extract was mixed and transferred to an autosampler vial for analysis.

Matrix calibration standards (20 to 1,000 ng sulfolane/mL) were prepared in male Sprague Dawley rat plasma similar to study samples except that 10 µL of sulfolane spiking solution was added in place of water. Matrix blanks (no sulfolane added) and quality control (QC) standards (50 and 500 ng sulfolane/mL) were prepared in corresponding study matrices. All samples were analyzed for sulfolane concentration via gas chromatography with mass spectrometry (GC/MS) using an Agilent 7890A (Agilent, Santa Clara, CA) GC/MS with an Agilent DB-5 column (30 m × 0.25 mm internal diameter, 0.25 µm film thickness). Study samples with responses greater than the highest calibration standard were diluted 5-fold with matrix or diluted up to 50-fold using both the matrix and the internal standard blank matrix extract.

### D.2.1 Instrumentation and Quantitation

A linear regression with 1/x^2^ weighting was used to relate the peak area ratio of sulfolane to the internal standard and sulfolane concentration. The concentration of sulfolane in each study sample was calculated from the peak area ratio, the linear regression equation, and a dilution factor, if necessary. The concentrations were reported as ng sulfolane/mL plasma.

The performance of the calibration curve was evaluated before the analysis of each sample set. A successful calibration was indicated by the following: correlation coefficient (r) ≥0.99; relative standard deviation (RSD) ≤15% (except at the limit of quantitation [LOQ] where RSD was ≤20%); relative error (RE) ≤15% (except at LOQ where RE was ≤20%). All calibration curves met acceptance criteria.

Data from study samples were considered valid if they were bracketed by valid QC sets. In general, each sample set, method blank, and control were bracketed by two QC sets, which consisted of a calibration blank and two concentrations of calibration standards (QC low and QC high). A QC set passed when the measured concentration for QC standards was within 15% of its nominal value. If the QC standard failed, it was necessary to reanalyze the bracketed samples. All QC standards were within 15% of nominal concentrations.