# Appendix A Chemical Characterization and Dose Formulation Studies

## A.1 Procurement and Characterization of Sulfolane

Sulfolane was obtained from Sigma-Aldrich (Milwaukee, WI) in a single lot (lot MKBN9784V). Identity, purity, and stability analyses were conducted by the analytical chemistry laboratory at RTI International (Research Triangle Park, NC) and the study laboratory at Battelle (Columbus, OH). Reports on analyses performed in support of the sulfolane studies are on file at the National Institute of Environmental Health Sciences (NIEHS).

Lot MKBN9784V was a solid to a gel at room temperature, formed a colorless liquid upon warming, and was consistent with the supplier’s Certificate of Analysis. The identity of the test lot was evaluated using infrared (IR) spectroscopy, ^1^H nuclear magnetic resonance (NMR) spectroscopy, ^13^C NMR spectroscopy, and ultra-high performance liquid chromatography (UHPLC) with high resolution mass spectrometry (MS). The IR, ^1^H NMR, and ^13^C NMR spectra (Figure A-1, Figure A-2, and Figure A-3, respectively) cohered with the structure of sulfolane and were consistent with reference spectra from the Sigma-Aldrich library (IR and ^1^H NMR)^35,36^ and the Spectral Database for Organic Compounds (^13^C NMR).^37^ UHPLC with high resolution MS further confirmed the identity of the test lot as sulfolane, as the observed molecular mass (121.0321 m/z) was within 2.5 m/z of the calculated molecular mass (121.0318 m/z). Elemental analyses were performed by Galbraith Laboratory (Knoxville, TN) to aid in identification. The relative amounts of carbon (39.51%), hydrogen (7.08%), and sulfur (26.34%) were within 6% of the theoretical values (39.98%, 6.71%, and 26.68%, respectively). An accurate determination of oxygen could not be made because of interference from the high elemental sulfur content. The boiling point (285°C) and density (1.31 g/cm^3^ at 21.9°C) measured by Galbraith Laboratory were consistent with literature values from the Hazardous Substance Data Bank (285°C and 1.26 g/cm^3^ at 30°C, respectively).^10^

Purity evaluation was conducted using gas chromatography (GC) with flame ionization detection (FID) (Table A-1, System A) and GC with MS detection (Table A-1, System B). The GC/FID chromatogram showed one major peak accounting for 99.9% of total peak area; no impurity peaks with areas ≥0.1% of the total integrated peak area were detected. The GC/MS spectrum for the major component was consistent with the library spectrum for sulfolane.^38^ Karl Fischer titration yielded a water content of 0.22%. The overall purity of the test lot was determined to be >99%. Because butadiene is a precursor of sulfolane synthesis, additional GC/MS analysis was conducted to determine whether butadiene was present at trace levels (Table A-1, System C). Butadiene was not present at ≥0.05% of the total ion chromatogram, with an analytical system limit of detection of butadiene at 12 ng/mL.

An accelerated stability study was previously conducted using a different lot (MKBH1265V, Sigma-Aldrich [Milwaukee, WI]) and was not repeated using lot MKBN9784V. The stability of lot MKBH1265V was confirmed for 14 days at frozen (−20°C), refrigerated (5°C), room (25°C), and elevated (60°C) temperatures when stored in amber glass vials sealed with Teflon^®^-lined caps.

One 30-gallon drum of lot MKBN9784V was warmed for 2.5 hours to liquify the contents. Once the chemical was liquified, the drum was rolled for approximately 5 minutes to homogenize the contents. A spigot was screwed into the drum, and it was placed on a drum cradle. The chemical was transferred to thirty 80-ounce amber glass bottles sealed with a nitrogen headspace for bulk storage at room temperature. Reanalysis of the bulk chemical was performed by the study laboratory prior to and after the 2-year study; no degradation was detected by GC/FID (Table A-1, System D).

## A.2 Preparation and Analysis of Dose Formulations

Dose formulations of sulfolane (lot MKBN9784V) in tap water (West Jefferson, OH municipal supply) were prepared approximately monthly at the study laboratory following the protocols outlined in Table A-2. Formulations were prepared at 0, 30, 100, 300, and 1,000 mg/L for both rats and mice (29 batches; May 2015–April 2017). For the rat study, two additional batches were prepared in May and June 2017. The formulations were stored refrigerated (5°C) in amber glass bottles sealed with Teflon-lined lids and were used within 42 days of preparation.

The stability of sulfolane formulations in tap water was determined by the analytical laboratory at RTI International using GC/FID (Table A-1, System E). Samples were prepared at 30 mg/L and stored at refrigerated (5°C) or room (25°C) temperatures. Stability was confirmed for 42 days at both refrigerated and room temperatures. An additional study of the 30 mg/L formulation under dosing conditions was conducted. A single test solution was stored in a clear glass bottle in an animal cage in a fume hood exposed to normal laboratory lighting. Stability was confirmed for 8 days under these simulated dosing conditions.

Periodic analyses of the preadministration and postadministration dose formulations of sulfolane were conducted every 2 to 3 months by the Battelle analytical laboratory using GC/FID (Table A-1, System F). Postadministration samples were collected from the animal rooms and formulation carboys. A 1,000 mg/L formulation was prepared on August 12, 2015, to replace the original preparation from July 23, 2015, which did not meet acceptance criteria and was deemed not suitable for use. With that exception, all other preadministration dose formulations were within 10% of the target concentrations (Table A-3). All postadministration samples were within 10% of the target concentrations with the following exceptions: The carboy samples of the 30 and 1,000 mg/L formulations prepared on May 4, 2015, were 10.9% and 10.2% below the target concentrations, respectively. The carboy samples of the 300 and 1,000 mg/L formulations prepared on September 21, 2015, were 10.2% and 13.0% below the target concentrations, respectively. The rat animal room sample of the 30 mg/L formulation prepared on July 23, 2015, was 10.5% below the target concentration, and the mouse animal room sample of the 300 mg/L formulation prepared on May 4, 2015, was 12.4% below the target concentration.

Table A-1 Gas Chromatography Systems Used in the Two-year Drinking Water Studies of Sulfolane

Detection System | Column | Carrier Gas | Oven Temperature Program
System A
Flame ionization (260°C) | J&W DB-WAX (15 m × 0.32 mm ID, 0.25 µm film thickness) | Helium at 1.5 mL/minute | 80°C for 1 minute, then 20°C/minute to 250°C, then held for 7 minutes at 250°C
System B
Mass spectrometry with electron impact ionization | J&W DB-5MS (30 m × 0.25 mm ID, 0.25 µm film thickness) | Helium at 1.0 mL/minute | 60°C for 3 minutes, then 30°C/minute to 270°C, then held for 2 minutes at 270°C
System C
Mass spectrometry | J&W DB-624 (30 m × 0.32 mm ID, 1.80 µm film thickness) | Helium at 1.5 mL/minute | 35°C for 3 minutes, then 30°C/minute to 245°C, then held for 5 minutes at 245°C
System D
Flame ionization (260°C) | J&W DB-WAX (15 m × 0.32 mm ID, 0.25 µm film thickness) | Helium at 1.5 mL/minute | 80°C for 1 minute, then 20°C/minute to 200°C, then held for 5 minutes at 200°C
System E
Flame ionization (260°C) | J&W DB-WAX (15 m × 0.32 mm ID, 0.25 µm film thickness) | Helium at 1.5 mL/minute | 80°C for 1 minute, then 20°C/minute to 200°C, then held for 3 minutes at 200°C
System F
Flame ionization (260°C) | J&W DB-WAX (15 m × 0.32 mm ID, 0.25 µm film thickness) | Helium at 1.5 mL/minute | 80°C for 1 minute, then 20°C/minute to 200°C, then held for 7 minutes at 200°C

ID = inner diameter.

Table A-2 Preparation and Storage of Dose Formulations Administered to Male and Female Rats and Mice in the Two-year Drinking Water Studies of Sulfolane

Preparation
For the 0 mg/L formulation, blank tap water vehicle was used. For remaining formulations, a target amount of test article was weighed into individually tared weighing containers. The weighed test article was transferred to the appropriate tared mixing drum containing ~80% of the target final volume of vehicle. The weighing container was rinsed three times with vehicle, and the rinses were added to the mixing drum. The vehicle was slowly added to the mixing drum to achieve the target final total weight. The mixing drum contents were mixed with a drum stirrer for ~10 minutes or until the test article was visibly in solution.
Chemical Lot Number
MKBN9784V (Sigma-Aldrich, Milwaukee, WI)
Maximum Storage Time
42 days
Storage Conditions
Stored in amber glass bottles sealed with Teflon^®^-lined lids at 5°C (refrigerated).
Analytical Laboratory
Battelle (Columbus, OH)
Study Laboratory
Battelle (West Jefferson, OH)

Table A-3 Results of Analyses of Dose Formulations Administered to Male and Female Rats and Mice in the Two-year Drinking Water Studies of Sulfolane

Date Prepared | Date Analyzed | Target Concentration (mg/L) | Determined Concentration (mg/L)^a^ | Difference from Target (%)
May 4, 2015 | May 5, 2015 | 0 | BLOQ | NA
| | 30 | 29.7 ± 0.2 | −1.1
| | 100 | 92.3 ± 0.3 | −7.7
| | 300 | 276 ± 10 | −8.1
| | 1,000 | 940 ± 48 | −6.0
July 23, 2015 | July 27, 2015 | 0 | BLOQ | NA
| | 30 | 30.5 ± 0.3 | 1.7
| | 30 | 29.0 ± 0.3 | −3.4
| | 100 | 90.8 ± 5.0 | −9.2
| | 100 | 98.7 ± 2.0 | −1.3
July 23, 2015 | July 30, 2015 | 300 | 305 ± 8 | 1.7
| | 300 | 299 ± 7 | −0.3
| | 1,000 | 933 ± 59 | −6.7
| | 1,000^b,c^ | 980 ± 33 | −2.0
September 21, 2015 | September 21, 2015 | 0 | BLOQ | NA
| | 30 | 29.1 ± 0.3 | −2.9
| | 30 | 28.3 ± 0.8 | −5.6
| | 100 | 91.7 ± 0.8 | −8.3
| | 100 | 96.8 ± 1.0 | −3.2
| | 300 | 284 ± 10 | −5.3
| | 300 | 279 ± 10 | −6.9
| | 1,000 | 905 ± NA^d^ | −9.5
| | 1,000 | 938 ± 64 | −6.2
December 8, 2015 | December 9, 2015 | 0 | BLOQ | NA
| | 30 | 30.1 ± 0.6 | 0.2
| | 30 | 30.4 ± 0.4 | 1.5
| | 100 | 97.5 ± 1.0 | −2.5
| | 100 | 103 ± 2 | 2.7
| | 300 | 295 ± 5 | −1.8
| | 300 | 286 ± 8 | −4.8
| | 1,000 | 1,010 ± 30 | 0.5
| | 1,000 | 980 ± 26 | −2.0
February 2, 2016 | February 4, 2016 | 0 | BLOQ | NA
| | 30 | 31.3 ± 0.4 | 4.2
| | 30 | 31.2 ± 0.8 | 3.9
| | 100 | 97.8 ± 1.0 | −2.2
| | 100 | 101 ± 2 | 1.3
| | 300 | 309 ± 6 | 3.0
| | 300 | 306 ± 13 | 2.1
| | 1,000 | 973 ± 8 | −2.7
| | 1,000 | 987 ± 20 | −1.3
April 26, 2016 | April 29, 2016 | 0 | BLOQ | NA
| | 30 | 29.2 ± 0.5 | −2.8
| | 30 | 29.7 ± 0.5 | −1.0
| | 100 | 97.8 ± 0.8 | −2.2
| | 100 | 97.3 ± 0.3 | −2.7
| | 300 | 298 ± 5 | −0.8
| | 300 | 301 ± 1 | 0.3
| | 1,000 | 988 ± 19 | −1.2
| | 1,000 | 977 ± 8 | −2.3
June 21, 2016 | June 23, 2016 | 0 | BLOQ | NA
| | 30 | 29.5 ± 0.1 | −1.8
| | 30 | 30.2 ± 0.4 | 0.8
| | 100 | 97.5 ± 0.9 | −2.5
| | 100 | 98.5 ± 0.0 | −1.5
| | 300 | 305 ± 1 | 1.8
| | 300 | 301 ± 5 | 0.5
| | 1,000 | 998 ± 10 | −0.2
| | 1,000 | 992 ± 8 | −0.8
September 13, 2016 | September 14, 2016 | 0 | BLOQ | NA
| | 30 | 29.4 ± 0.2 | −1.9
| | 30 | 29.3 ± 0.2 | −2.2
| | 100 | 98.0 ± 0.5 | −2.0
| | 100 | 96.3 ± 0.3 | −3.7
| | 300 | 296 ± 3 | −1.2
| | 300 | 290 ± 4 | −3.5
| | 1,000 | 977 ± 8 | −2.3
| | 1,000 | 972 ± 15 | −2.8
November 8, 2016 | November 11, 2016 | 0 | BLOQ | NA
| | 30 | 29.2 ± 0.6 | −2.8
| | 30 | 28.5 ± 0.9 | −5.1
| | 100 | 94.7 ± 2.3 | −5.3
| | 100 | 93.0 ± 0.5 | −7.0
| | 300 | 293 ± 7 | −2.5
| | 300 | 290 ± 2 | −3.4
| | 1,000 | 967 ± 20 | −3.3
| | 1,000 | 968 ± 14 | −3.2
February 2, 2017 | February 2, 2017 | 0 | BLOQ | NA
| | 30 | 29.6 ± 0.7 | −1.3
| | 30 | 29.6 ± 0.5 | −1.3
| | 100 | 101 ± 1 | 0.5
| | 100 | 102 ± 1 | 1.7
| | 300 | 306 ± 2 | 1.9
| | 300 | 299 ± 6 | −0.4
| | 1,000 | 1,010 ± 10 | 0.5
| | 1,000 | 977 ± 18 | −2.3
March 28, 2017 | March 30, 2017 | 0 | BLOQ | NA
| | 30 | 29.2 ± 0.2 | −2.7
| | 30 | 28.8 ± 0.3 | −3.9
| | 100 | 95.0 ± 1.3 | −5.0
| | 100 | 97.3 ± 1.0 | −2.7
| | 300 | 288 ± 6 | −4.1
| | 300 | 290 ± 1 | −3.2
| | 1,000 | 972 ± 15 | −2.8
| | 1,000 | 995 ± 15 | −0.5
June 20, 2017^e^ | June 26, 2017 | 0 | BLOQ | NA
| | 30 | 30.7 ± 0.6 | 2.3
| | 100 | 101 ± 1 | 1.3
| | 300 | 292 ± 5 | −2.6
| | 1,000 | 918 ± 8 | −8.2
Carboy Samples
May 4, 2015 | June 15, 2015 | 0 | BLOQ | NA
| | 30 | 26.7 ± 0.2 | −10.9
| | 100 | 96.2 ± 0.3 | −3.8
| | 300 | 295 ± 3 | −1.8
| | 1,000 | 898 ± 6 | −10.2
July 23, 2015 | September 3, 2015 | 0 | BLOQ | NA
| | 30 | 27.7 ± 0.7 | −7.7
| | 100 | 93.8 ± 1.4 | −6.2
| | 300 | 276 ± 2 | −8.1
| | 1,000^b^ | 987 ± 20 | −1.3
September 21, 2015 | October 28, 2015 | 0 | BLOQ | NA
| | 30 | 27.8 ± 0.2 | −7.5
| | 100 | 91.5 ± 1.3 | −8.5
| | 300 | 269 ± 4 | −10.2
| | 1,000 | 870 ± 10 | −13.0
December 8, 2015 | January 20, 2016 | 0 | BLOQ | NA
| | 30 | 29.4 ± 0.3 | −2.0
| | 100 | 95.8 ± 0.8 | −4.2
| | 300 | 316 ± 8 | 5.3
| | 1,000 | 973 ± 10 | −2.7
June 21, 2016 | August 3, 2016 | 0 | BLOQ | NA
| | 30 | 29.7 ± 1.4 | −1.0
| | 100 | 103 ± 2 | 3.3
| | 300 | 310 ± 3 | 3.5
| | 1,000 | 1,050 ± 10 | 4.7
February 2, 2017 | March 16, 2017 | 0 | BLOQ | NA
| | 30 | 28.7 ± 0.3 | −4.3
| | 100 | 95.3 ± 0.8 | −4.7
| | 300^f^ | 287 ± 6 | −4.4
| | 1,000^f^ | 952 ± 8 | −4.8
Animal Room Samples (Rats)
May 4, 2015 | June 15, 2015 | 0 | BLOQ | NA
| | 30 | 29.8 ± 0.5 | −0.6
| | 100 | 97.5 ± 0.0 | −2.5
| | 300 | 283 ± 8 | −5.6
| | 1,000 | 935 ± 26 | −6.5
July 23, 2015 | September 3, 2015 | 0 | BLOQ | NA
| | 30 | 26.9 ± 0.6 | −10.5
| | 100 | 93.8 ± 0.3 | −6.2
| | 300 | 278 ± 1 | −7.4
| | 1,000^b^ | 972 ± 13 | −2.8
September 21, 2015 | October 28, 2015 | 0 | BLOQ | NA
| | 30 | 27.5 ± 0.2 | −8.3
| | 100 | 96.2 ± 0.3 | −3.8
| | 300 | 270 ± 4 | −10.0
| | 1,000 | 912 ± 6 | −8.8
December 8, 2015 | January 20, 2016 | 0 | BLOQ | NA
| | 30 | 28.8 ± 0.3 | −3.9
| | 100 | 92.8 ± 2.5 | −7.2
| | 300 | 296 ± 2 | −1.2
| | 1,000 | 955 ± 13 | −4.5
June 21, 2016 | August 3, 2016 | 0 | BLOQ | NA
| | 30 | 31.0 ± 1.8 | 3.2
| | 100 | 101 ± 2 | 1.2
| | 300 | 306 ± 3 | 1.9
| | 1,000 | 1,050 ± 20 | 4.7
February 2, 2017 | March 16, 2017 | 0 | BLOQ | NA
| | 30 | 28.9 ± 0.2 | −3.7
| | 100 | 96.0 ± 1.3 | −4.0
| | 300^f^ | 286 ± 6 | −4.7
| | 1,000^f^ | 970 ± 13 | −3.0
Animal Room Samples (Mice)
May 4, 2015 | June 15, 2015 | 0 | BLOQ | NA
| | 30 | 30.1 ± 0.2 | 0.3
| | 100 | 99.2 ± 0.3 | −0.8
| | 300 | 263 ± 10 | −12.4
| | 1,000 | 927 ± 8 | −7.3
July 23, 2015 | September 3, 2015 | 0 | BLOQ | NA
| | 30 | 27.6 ± 1.0 | −8.1
| | 100 | 91.5 ± 2.8 | −8.5
| | 300 | 276 ± 5 | −7.9
| | 1,000^b^ | 982 ± 8 | −1.8
September 21, 2015 | October 28, 2015 | 0 | BLOQ | NA
| | 30 | 27.7 ± 0.1 | −7.7
| | 100 | 91.2 ± 0.8 | −8.8
| | 300 | 279 ± 8 | −7.0
| | 1,000 | 922 ± 25 | −7.8
December 8, 2015 | January 20, 2016 | 0 | BLOQ | NA
| | 30 | 29.3 ± 0.3 | −2.3
| | 100 | 97.2 ± 0.6 | −2.8
| | 300 | 289 ± 9 | −3.6
| | 1,000 | 930 ± 33 | −7.0
June 21, 2016 | August 3, 2016 | 0 | BLOQ | NA
| | 30 | 30.6 ± 0.4 | 2.0
| | 100 | 103 ± 1 | 3.0
| | 300 | 275 ± 9 | −8.4
| | 1,000 | 1,060 ± 10 | 6.0
February 2, 2017 | March 16, 2017 | 0 | BLOQ | NA
| | 30 | 29.1 ± 0.2 | −3.0
| | 100 | 96.7 ± 0.8 | −3.3
| | 300^f^ | 279 ± 5 | −6.9
| | 1,000^f^ | 960 ± 13 | −4.0

BLOQ = below the limit of quantification; NA = not applicable.

^a^ Data are presented as mean ± standard deviation of triplicate analysis.

^b^ Prepared August 12, 2015.

^c^ Analyzed August 12, 2015.

^d^ The first replicate of three was deemed to be an outlier according to Q-test analysis and was excluded from the calculations.

^e^ Prepared only for the rat study.

^f^ Analyzed March 20, 2017.

Figure A-1

Infrared Absorption Spectrum of Sulfolane

Figure A-2

^1^H Nuclear Magnetic Resonance Spectrum of Sulfolane

Figure A-3

^13^C Nuclear Magnetic Resonance Spectrum of Sulfolane