# Publication Details

Publisher: National Toxicology Program

Publishing Location: Research Triangle Park, NC

ISSN: 2378-8925

DOI: https://doi.org/10.22427/NTP-TR-604

Report Series: NTP Technical Report Series

Report Series Number: 604

Official citation: National Toxicology Program (NTP). 2024. NTP technical report on the toxicology and carcinogenesis study of triclosan (CASRN 3380-34-5) administered dermally to B6C3F1/N mice. Research Triangle Park, NC: National Toxicology Program. Technical Report 604.