# Peer Review

The National Toxicology Program (NTP) conducted a peer review of the draft NTP Technical Report on the Toxicology and Carcinogenesis Study of Triclosan (CASRN 3380-34-5) Administered Dermally to B6C3F1/N Mice by letter in November 2022 by the experts listed below. Reviewer selection and document review followed established NTP practices. The reviewers were charged to:

1. Peer review the draft NTP Technical Report on the Toxicology and Carcinogenesis Study of Triclosan (CASRN 3380-34-5) Administered Dermally to B6C3F1/N Mice.
2. Comment on NTP’s conclusions and interpretations of the data.

NTP carefully considered reviewer comments in finalizing this report.

## Peer Reviewers

- Lydia Andrews-Jones, D.V.M., Ph.D., DACVP
  Director, Pathology
  AbbVie, Irvine, California, USA
- Emanuela Corsini, Ph.D.
  Full Professor
  Università degli Studi di Milano, Milan, Italy
- James Klaunig, Ph.D.
  Professor Emeritus
  Indiana University, Bloomington, Indiana, USA