# Collaborators

- National Center for Toxicological Research, U.S. Food and Drug Administration, Jefferson, Arkansas, USA
  Conducted study, evaluated and interpreted results and pathology findings, reported findings, and prepared the study report
  J.L. Fang, Ph.D., Study Scientist
  F.A. Beland, Ph.D., Co-investigator
  G.R. Olson, D.V.M., Ph.D., Study Pathologist
  M.M. Vanlandingham, A.S., Study Coordinator
- Conducted prestart chemistry activities, dose formulations, and biological sample chemistry analyses
  M.S. Bryant, Ph.D., Principal Investigator
  M. Chidambaram, Ph.D.
  P. Chitranshi, Ph.D.
  G. Gamboa da Costa, Ph.D.
  L. Loulotková, Ph.D.
  A. Matson, B.S.
- Conducted statistical analyses
  R.P. Felton, M.S., Principal Investigator
  B.E. Juliar, M.A., M.S.
  P.M. Maisha, M.S.
  B.T. Thorn, M.S.
- Conducted quality assurance audits
  J.M. Fowler, B.S.
- Division of Translational Toxicology, National Institute of Environmental Health Sciences, Research Triangle Park, North Carolina, USA
  Reviewed and evaluated the technical report and interpreted results and pathology findings
  C.R. Blystone, Ph.D.
  M.F. Cesta, D.V.M., Ph.D.
  H.C. Cunny, Ph.D.
  G.K. Roberts, Ph.D.
  K.A. Shipkowski, Ph.D.
  K.R. Shockley, Ph.D.
  V.L. Sutherland, Ph.D.
  S. Waidyanatha, Ph.D.
  N.J. Walker, Ph.D.
- Provided oversight for data management
  J.M. Fostel, Ph.D.
- Experimental Pathology Laboratories, Inc., Research Triangle Park, North Carolina, USA
  Provided pathology review
  K.Y. Cimon, D.V.M., M.S.
  R.A. Miller, D.V.M., Ph.D.
  E.M. Quist, D.V.M., Ph.D.
  T.J. Steinbach, D.V.M.
- Coordinated Pathology Working Group on 2-year mice (March 21, 2017)
  T.J. Steinbach, D.V.M.
- ICF, Reston, Virginia, USA
  Conducted technical writing and data integration and ensured report quality
  L.M. Prince, Ph.D.