# References

1 Jones RD, Jampani HB, Newman JL, Lee AS. Triclosan: A review of effectiveness and safety in health care settings. Am J Infect Control. 2000; 28(2):184–196. 10.1067/mic.2000.102378 10760227
2 Fang JL, Stingley RL, Beland FA, Harrouk W, Lumpkins DL, Howard P. Occurrence, efficacy, metabolism, and toxicity of triclosan. J Environ Sci Health C Environ Carcinog Ecotoxicol Rev. 2010; 28(3):147–171. 10.1080/10590501.2010.504978 20859822
3 Rodricks JV, Swenberg JA, Borzelleca JF, Maronpot RR, Shipp AM. Triclosan: A critical review of the experimental data and development of margins of safety for consumer products. Crit Rev Toxicol. 2010; 40(5):422–484. 10.3109/10408441003667514 20377306
4 Fang JL, Vanlandingham MM, Juliar BE, Olson GR, Patton RE, Beland FA. Dose–response assessment of the dermal toxicity of triclosan in B6C3F1 mice. Toxicol Res (Camb). 2015; 4(4):867–877. 10.1039/C4TX00152D
5 Fang JL, Vanlandingham M, da Costa GG, Beland FA. Absorption and metabolism of triclosan after application to the skin of B6C3F1 mice. Environ Toxicol. 2016; 31(5):609–623. 10.1002/tox.22074 25410937
6 Tulp MTM, Sundström G, Martron LBJM, Hutzinger O. Metabolism of chlorodiphenyl ethers and Irgasan DP 300. Xenobiotica. 1979; 9(2):65–77. 10.3109/00498257909038708 433312
7 Lyman FL, Furia T. Toxicology of 2, 4, 4′-trichloro-2′-hydroxy-diphenyl ether. IMS Ind Med Surg. 1969; 38(2):64–71. 5250173
8 U.S. Environmental Protection Agency (USEPA). Health effects test guidelines: OPPTS 870.4300: Combined chronic toxicity/carcinogenicity. Washington, DC: U.S Environmental Protection Agency, Prevention, Pesticides and Toxic Substances; 1998. EPA Report No. EPA 712-C-98-212. https://nepis.epa.gov/Exe/ZyPURL.cgi?Dockey=P100ID4F.txt
9 Maronpot RR, Boorman GA. Interpretation of rodent hepatocellular proliferative alterations and hepatocellular tumors in chemical safety assessment. Toxicol Pathol. 1982; 10(2):71–78. 10.1177/019262338201000210 28094716
10 Boorman GA, Haseman JK, Waters MD, Hardisty JF, Sills RC. Quality review procedures necessary for rodent pathology databases and toxicogenomic studies: The National Toxicology Program experience. Toxicol Pathol. 2002; 30(1):88–92. 10.1080/01926230252824752 11890481
11 Brix AE, Hardisty JF, McConnell EE. Combining neoplasms for evaluation of rodent carcinogenesis studies. In: Hsu CH, Stedeford T, editors. Cancer Risk Assessment: Chemical Carcinogenesis, Hazard Evaluation, and Risk Quantification. Hoboken, NJ: Wiley; 2010. p. 699–715. 10.1002/9780470622728.ch28
12 Kaplan EL, Meier P. Nonparametric estimation from incomplete observations. J Am Stat Assoc. 1958; 53(282):457–481. 10.1080/01621459.1958.10501452
13 Tarone RE. Tests for trend in life table analysis. Biometrika. 1975; 62(3):679–690. 10.1093/biomet/62.3.679
14 Cox DR. Regression models and life-tables. J R Stat Soc Series B Stat Methodol. 1972; 34(2):187–202. 10.1111/j.2517-6161.1972.tb00899.x
15 Bailer AJ, Portier CJ. Effects of treatment-induced mortality and tumor-induced mortality on tests for carcinogenicity in small samples. Biometrics. 1988; 44(2):417–431. 10.2307/2531856 3390507
16 Piegorsch WW, Bailer AJ. Statistics for environmental biology and toxicology: Section 6.3.2. London, UK: Chapman and Hall; 1997.
17 Portier CJ, Bailer AJ. Testing for increased carcinogenicity using a survival-adjusted quantal response test. Fundam Appl Toxicol. 1989; 12(4):731–737. 10.1016/0272-0590(89)90004-3 2744275
18 Portier CJ, Hedges JC, Hoel DG. Age-specific models of mortality and tumor onset for historical control animals in the National Toxicology Program’s carcinogenicity experiments. Cancer Res. 1986; 46(9):4372–4378. 3731095
19 Bieler GS, Williams RL. Ratio estimates, the delta method, and quantal response tests for increased carcinogenicity. Biometrics. 1993; 49(3):793–801. 10.2307/2532200 8241374
20 Nam JM. A simple approximation for calculating sample sizes for detecting linear trend in proportions. Biometrics. 1987; 43(3):701–705. 10.2307/2532006 3663825
21 Littell RC, Milliken GA, Stroup WW, Wolfinger RD, Schabenberger O. SAS for mixed models. 2nd ed. Cary, NC: SAS Institute; 2006.
22 Hsu JC. The factor analytic approach to simultaneous inference in the general linear mode. J Comput Graph Stat. 1992; 1(2):151–168. 10.1080/10618600.1992.10477011
23 Haseman JK. Value of historical controls in the interpretation of rodent tumor data. Drug Inf J. 1992; 26(2):191–200. 10.1177/009286159202600210
24 Haseman JK. Data analysis: Statistical analysis and use of historical control data. Regul Toxicol Pharmacol. 1995; 21(1):52–59. 10.1006/rtph.1995.1009 7784636
25 Haseman JK, Rao GN. Effects of corn oil, time-related changes, and inter-laboratory variability on tumor occurrence in control Fischer 344 (F344/N) rats. Toxicol Pathol. 1992; 20(1):52–60. 10.1177/019262339202000107 1411131
26 U.S. Food and Drug Administration (FDA). 21 CFR Part 58. https://www.accessdata.fda.gov/scripts/cdrh/cfdocs/cfcfr/CFRSearch.cfm?CFRPart=58
27 National Toxicology Program (NTP). TR-604: Pathology tables, survival and growth curves from NTP long-term studies. Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Toxicology Program; 2024. 10.22427/NTP-DATA-TR-604
28 Paul KB, Thompson JT, Simmons SO, Vanden Heuvel JP, Crofton KM. Evidence for triclosan-induced activation of human and rodent xenobiotic nuclear receptors. Toxicol In Vitro. 2013; 27(7):2049–2060. 10.1016/j.tiv.2013.07.008 23899473
29 Wang Z, Li X, Klaunig JE. Investigation of the mechanism of triclosan induced mouse liver tumors. Regul Toxicol Pharmacol. 2017; 86:137–147. 10.1016/j.yrtph.2017.03.001 28267557
30 Wu Y, Wu Q, Beland FA, Ge P, Manjanatha MG, Fang JL. Differential effects of triclosan on the activation of mouse and human peroxisome proliferator-activated receptor alpha. Toxicol Lett. 2014; 231(1):17–28. 10.1016/j.toxlet.2014.09.001 25193434
31 Tang Y, Vanlandingham MM, Wu Y, Beland FA, Olson GR, Fang JL. Role of peroxisome proliferator-activated receptor alpha (PPARα) and PPARα-mediated species differences in triclosan-induced liver toxicity. Arch Toxicol. 2018; 92(11):3391–3402. 10.1007/s00204-018-2308-7 30238133
32 Yueh MF, Taniguchi K, Chen S, Evans RM, Hammock BD, Karin M, Tukey RH. The commonly used antimicrobial additive triclosan is a liver tumor promoter. Proc Natl Acad Sci U S A. 2014; 111(48):17200–17205. 10.1073/pnas.1419119111 25404284
33 Fang JL, Vaca CE. Detection of DNA adducts of acetaldehyde in peripheral white blood cells of alcohol abusers. Carcinogenesis. 1997; 18(4):627–632. 10.1093/carcin/18.4.627 9111191
34 Balbo S, Hashibe M, Gundy S, Brennan P, Canova C, Simonato L, Merletti F, Richiardi L, Agudo A, Castellsagué X, et al. N2-ethyldeoxyguanosine as a potential biomarker for assessing effects of alcohol consumption on DNA. Cancer Epidemiol Biomarkers Prev. 2008; 17(11):3026–3032. 10.1158/1055-9965.EPI-08-0117 18990745
35 Terashima I, Matsuda T, Fang TW, Suzuki N, Kobayashi J, Kohda K, Shibutani S. Miscoding potential of the N2-ethyl-2′-deoxyguanosine DNA adduct by the exonuclease-free Klenow fragment of Escherichia coli DNA polymerase I. Biochemistry. 2001; 40(13):4106–4114. 10.1021/bi002719p 11300791
36 Scientific Committee on Consumer Products (SCCP). Opinion on triclosan: Colipa n° P32. Brussels, Belgium: European Commission, Health and Consumer Protection, Directorate-General; 2009. SCCP/1192/08. https://ec.europa.eu/health/ph_risk/committees/04_sccp/docs/sccp_o_166.pdf
37 Lee JD, Lee JY, Kwack SJ, Shin CY, Jang HJ, Kim HY, Kim MK, Seo DW, Lee BM, Kim KB. Risk assessment of triclosan, a cosmetic preservative. Toxicol Res. 2019; 35(2):137–154. 10.5487/TR.2019.35.2.137 31015896
38 Queckenberg C, Meins J, Wachall B, Doroshyenko O, Tomalik-Scharte D, Bastian B, Abdel-Tawab M, Fuhr U. Absorption, pharmacokinetics, and safety of triclosan after dermal administration. Antimicrob Agents Chemother. 2010; 54(1):570–572. 10.1128/AAC.00615-09 19822703
39 Sandborgh-Englund G, Adolfsson-Erici M, Odham G, Ekstrand J. Pharmacokinetics of triclosan following oral ingestion in humans. J Toxicol Environ Health A. 2006; 69(20):1861–1873. 10.1080/15287390600631706 16952905
40 Lin YJ. Buccal absorption of triclosan following topical mouthrinse application. Am J Dent. 2000; 13(4):215–217. 11763935