# Conclusions

Under the conditions of this 2-year dermal study, there was some evidence of carcinogenic activity of triclosan in male B6C3F1/N mice based on the increased incidences of hepatocellular adenoma or carcinoma (combined). There was equivocal evidence of carcinogenic activity of triclosan in female B6C3F1/N mice based on higher occurrences of pancreatic islet adenomas.

Dermal administration of triclosan resulted in increased incidences of nonneoplastic epidermal lesions at the site of application in male and female mice.