# Discussion

In the current 2-year mouse study, the survival of all dosed groups was similar to that of the vehicle control groups. There were significant decreases in body weight in the 12.5 mg triclosan/kg body weight/day (mg/kg/day) group for both sexes; nonetheless, the decrease was modest and did not exceed 8%. Minimal to mild gross lesions of the skin (dry flaking skin, scratches, thickened skin, and dark pigmentation) were observed in all dosed groups. The severity of these lesions was not sufficient to cause the removal of any animal from the study. There were no neoplasms observed at the site of triclosan application.

The dermal administration of triclosan resulted in increased incidences of hepatocellular neoplasms when compared to the vehicle control group, which is the most appropriate comparison. A positive trend in the incidence of hepatocellular carcinoma was noted in male mice, with the increase becoming significant at ≥5.8 mg/kg/day. The incidence of hepatocellular carcinoma in the vehicle control group was within the historical control range (10%–42%, average 25.16% for all routes of exposure), and the incidence in the 5.8 and 12.5 mg/kg/day groups was outside the historical control range. There was also a significant increase in the incidence of hepatocellular adenoma at 2.7 mg/kg/day. The incidence of hepatocellular adenoma or carcinoma (combined) was significantly increased in the ≥2.7 mg/kg/day groups, with a positive trend. Together these data indicate carcinogenic activity from the exposure to triclosan. The unusually high incidences of hepatocellular carcinoma and hepatocellular adenoma or carcinoma (combined) in the untreated control group (56% and 85%, respectively), compared to the vehicle control group (31% and 65%, respectively), and a lack of exposure-related nonneoplastic lesions in the liver, reduced confidence in the strength of the evidence. The incidence of hepatocellular carcinoma in the vehicle control males was within the historical control range, and the cause of the high incidence in the untreated control group, which was outside the historical control range, is unknown. Taken together, the significantly increased incidence of hepatocellular adenoma or carcinoma (combined) in male mice, relative to the vehicle control group, was some evidence of carcinogenic activity. This response did not occur in female mice.

The hepatocellular carcinoma incidence in untreated control male mice in the current study exceeded the NTP 5-year historical control incidence for all routes of exposure but is within the historical control range for dermal studies of Taconic B6C3F1 mice fed the NTP-2000 diet conducted between 1996 and 2010. The reason for the unusually high hepatocellular carcinoma incidence in the untreated control males in the current study is not known. However, the untreated control animals were not subjected to the same handling and dosing as the other groups, and this result does not negate the fact that there was a dose-related hepatocellular response in male mice administered triclosan compared to the vehicle control group.

Hepatocellular neoplasms have been reported in male and female CD-1 mice administered triclosan at dietary concentrations equivalent to doses of ≥30 mg/kg/day (summarized in Rodricks et al.^3^). Benchmark dose (BMD) modeling of hepatocellular carcinoma in the male B6C3F1/N mice indicated that the benchmark dose lower confidence limit (BMDL_10_) ranged from 1.1 to 2.4 mg/kg/day, which was similar to that of epidermal hyperplasia.

The mechanism for the hepatic neoplasm induction in the current study is not known; however, evidence has been presented for a mode of action involving peroxisome proliferator-activated receptor alpha (PPARα) and/or the constitutive androstane receptor (CAR).^3,28,29^ Other studies have shown that triclosan activates mouse, but not human, PPARα^30^ and that triclosan induces hepatocyte proliferation in wild type C57BL/6 mice but not in mice transfected with human PPARα.^31^

Triclosan has been shown to accelerate the development of hepatocellular carcinoma in male C57BL/6 Car^+/−^ and C57BL/6 Car^−/−^ mice initiated with N,N-diethylnitrosamine.^32^ This response was attributed to triclosan enhancing liver fibrosis and proliferation. Ethanol is metabolized to acetaldehyde, which reacts with DNA to result in a Schiff base that can be reduced to N^2^-ethyldeoxyguanosine.^33,34^ The possibility exists that exposure to ethanol may result in tumor initiation through the formation of N^2^-ethyldeoxyguanosine, a DNA adduct that is known to miscode,^35^ and the coadministration of triclosan could serve as a tumor promoter. Although the incidence of hepatic neoplasms was lower in the vehicle control group than in the untreated control group in the current study, that lower incidence is of unknown origin. In addition to hepatocellular carcinoma in male B6C3F1/N mice, triclosan induced a positive trend in pancreatic islet adenoma in female B6C3F1/N mice. Pancreatic islet adenoma is a rare neoplasm in female B6C3F1/N mice. In NTP 2-year studies conducted using Taconic B6C3F1/N mice and the NTP-2000 diet, control female mice have a mean incidence of 0.38% (range: 0%–2%) for all routes of exposure. Although there was a positive trend in the incidence of pancreatic islet adenoma, the occurrence of pancreatic islet adenomas and carcinomas in the control groups, along with the lack of exposure-related preneoplastic lesions, lowered confidence in the strength of the evidence. This was considered to be equivocal evidence of carcinogenic activity.

Neoplasms were not detected at the site of triclosan application in either sex. Histopathological examination of the site of triclosan application indicated the presence of epidermal hyperplasia in both sexes and epidermal suppurative inflammation and ulceration in male mice. Male mice had a significant increase in the incidences of epidermal hyperplasia at doses ≥2.7 mg/kg/day; in female mice, the increase became significant at 1.25 mg/kg/day. The increases in the incidences of epidermal suppurative inflammation and ulceration became significant at 12.5 mg/kg/day in male mice. BMD modeling of the skin lesions indicated that the BMDL_10_ was 0.88–2.8 mg/kg/day for epidermal hyperplasia in male mice and 1.5–3.0 mg/kg/day in female mice. These BMDL_10_ values are lower than those obtained in a previous 13-week dermal study.^4^ They are also lower than the BMDL_10_ of 47 mg/kg/day, determined from kidney toxicity in hamsters, which was used to calculate margins of safety for triclosan.^3^ Likewise, they are also lower than the 12 mg/kg/day no-observed-adverse-effect level (NOAEL), determined from hepatotoxicity and decreased spleen weights of female rats, which was used by the Scientific Committee on Consumer Products^36^ and Lee et al.^37^ in their calculations of margins of safety for exposure to triclosan, or a NOAEL of 75 mg/kg/day determined from lifetime studies in hamsters, which was used to calculate the margin of safety following dermal administration of triclosan.^38^

Male B6C3F1 mice receiving a single dermal administration of 10 mg/kg triclosan had a maximum plasma concentration (C_max_) of 26 μM, and mice receiving 100 mg/kg triclosan had a C_max_ of 188 μM.^5^ These data suggest that mice receiving 1 mg/kg triclosan, a value similar to the BMDL_10_ values for epidermal hyperplasia, would have a C_max_ of approximately 2 μM. Humans exposed to a single oral dose of 4 mg triclosan had plasma concentrations of approximately 1 μM.^39^ Likewise, oral exposure to 0.7 mg triclosan resulted in plasma concentrations of approximately 0.3 μM^40^; thus, dermal exposure equivalent to the BMDL_10_ values for epidermal hyperplasia in mice is expected to result in plasma concentrations that could occur in people who use mouthwash products containing triclosan.