# Results

## Data Availability

All study data were evaluated. Data relevant for evaluating toxicological findings are presented here. All study data are available in the National Toxicology Program (NTP) Chemical Effects in Biological Systems (CEBS) database: https://doi.org/10.22427/NTP-DATA-TR-604.^27^

## Mice

### Two-year Study

Estimates of survival probabilities for mice are shown in Table 2 and in the Kaplan-Meier survival curves (Figure 2). The survival of all dosed groups of male and female mice was similar to that of the vehicle control group.

Table 2 Summary of Survival of Male and Female Mice in the Two-year Dermal Study of Triclosan

| Untreated Control | Vehicle Control | 1.25 mg/kg/day | 2.7 mg/kg/day | 5.8 mg/kg/day | 12.5 mg/kg/day
Male
Animals Initially in Study | 48 | 48 | 48 | 48 | 48 | 48
Moribund | 14 | 11 | 18 | 12 | 19 | 17
Accidental Deaths | 0 | 1 | 0 | 0 | 0 | 0
Natural Deaths | 3 | 1 | 0 | 2 | 1 | 0
Animals Surviving to Study Termination | 31 | 35 | 30 | 34 | 28 | 31
Percent Probability of Survival at Study Termination^a^ | 64.6 | 74.5 | 62.5 | 70.8 | 58.3 | 64.6
Survival (Days)^b^ | 676.7 ± 11.7 | 682.7 ± 16.6 | 671.8 ± 14.2 | 695.2 ± 9.8 | 671.2 ± 13.4 | 671.5 ± 15.0
Survival Analysis^c^ | –^d^ | p = 0.527 | p = 0.259 | p = 0.876 | p = 0.138 | p = 0.353
Female
Animals Initially in Study | 48 | 48 | 48 | 48 | 48 | 48
Moribund | 15 | 12 | 18 | 17 | 8 | 11
Natural Deaths | 0 | 1 | 1 | 0 | 3 | 2
Animals Surviving to Study Termination | 33 | 35 | 29 | 31 | 37 | 35
Percent Probability of Survival at Study Termination | 68.8 | 72.9 | 60.4 | 64.6 | 77.1 | 72.9
Survival (Days) | 691.6 ± 10.0 | 694.4 ± 10.2 | 674.7 ± 13.4 | 691.7 ± 9.3 | 678.1 ± 18.2 | 696.4 ± 9.3
Survival Analysis | – | p = 0.445N | p = 0.248 | p = 0.543 | p = 0.902N | p = 1.000N

^a^ Kaplan-Meier determinations.

^b^ Mean of all deaths (uncensored, censored, and study termination) ± standard error.

^c^ The result of the Tarone trend test is in the vehicle control group column, the results of the Cox proportional hazards pairwise comparisons to the vehicle control group are in the dosed group columns. A negative trend or lower mortality in a dose group is indicated by N.

^d^ No trend or pairwise statistical tests were performed to compare the untreated control group to the vehicle control group.

Figure 2

Kaplan-Meier Survival Curves for Male and Female Mice in the Two-year Dermal Study of Triclosan

Survival curves are shown for (A) males and (B) females.

At the site of application, minimal to mild skin lesions, including cuts, scratches, dark pigmentation, dry skin, flaking, sore, and tissue mass, were observed (Appendix E). Scratches were considered to be dose-related in both sexes. Dry skin and flaking either did not occur or occurred at a low incidence except in the 12.5 mg/kg/day male and female groups. Dark pigmentation was considered to be related to vehicle administration, and all other lesions were not considered to be related to vehicle or triclosan administration. These lesions were not considered sufficiently severe to require early termination of any of the mice in the study.

In male mice, dermal administration of triclosan over the full 2 years of the study caused a negative trend in body weights, with the decrease being significant in the 12.5 mg/kg/day group relative to the vehicle control group (Table 3; Figure 3). Compared to the vehicle control group, the decreases in the body weights of male mice dosed with 12.5 mg/kg/day never exceeded 7%. In female mice, dermal administration of triclosan over the full 2 years of the study caused a negative trend in body weights, with the decrease being significant in the 12.5 mg/kg/day group relative to the vehicle control group (Table 4; Figure 3). Compared to the vehicle control group, the decreases in the body weights of female mice dosed with 12.5 mg/kg/day never exceeded 8%.

Table 3 Summary of Survival and Body Weights of Male Mice in the Two-year Dermal Study of Triclosan

Study Week^a^ | Untreated Control | | Vehicle Control | | | 1.25 mg/kg/day | | | 2.7 mg/kg/day | | | 5.8 mg/kg/day | | | 12.5 mg/kg/day
Study Week^a^ | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls)^b^ | No. of Survivors | Av Wt. (g) | Wt. (% of Controls)^c^ | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls)^c^ | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls)^c^ | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls)^c^ | No. of Survivors
1 | 23.7 | 48 | 23.0 | 97 | 48 | 23.6 | 102 | 48 | 23.2 | 101 | 48 | 23.4 | 102 | 48 | 23.4 | 101 | 48
4 | 27.2 | 48 | 26.9 | 99 | 48 | 27.3 | 101 | 48 | 26.8 | 99 | 48 | 27.0 | 100 | 48 | 26.8 | 100 | 48
8 | 30.2 | 48 | 30.3 | 100 | 47 | 30.2 | 100 | 48 | 29.9 | 99 | 48 | 30.6 | 101 | 48 | 30.4 | 101 | 48
12 | 33.7 | 48 | 33.2 | 98 | 47 | 33.4 | 101 | 48 | 32.9 | 99 | 48 | 34.7 | 104 | 48 | 33.6 | 101 | 48
16 | 37.0 | 48 | 35.6 | 96 | 47 | 36.2 | 102 | 48 | 35.9 | 101 | 48 | 36.9 | 104 | 48 | 35.7 | 101 | 48
20 | 38.4 | 48 | 37.8 | 98 | 47 | 38.6 | 102 | 48 | 38.0 | 101 | 48 | 38.6 | 102 | 48 | 37.5 | 99 | 48
24 | 41.4 | 48 | 40.8 | 99 | 47 | 41.7 | 102 | 48 | 40.6 | 100 | 48 | 41.7 | 102 | 48 | 40.5 | 99 | 48
28 | 43.9 | 48 | 42.9 | 98 | 47 | 43.4 | 101 | 48 | 42.6 | 99 | 48 | 43.6 | 102 | 48 | 42.2 | 99 | 48
32 | 45.5 | 48 | 44.5 | 98 | 47 | 45.3 | 102 | 48 | 43.9 | 99 | 48 | 45.3 | 102 | 48 | 43.3 | 98 | 48
36 | 47.1 | 48 | 45.1 | 96 | 47 | 46.7 | 104 | 48 | 45.1 | 100 | 48 | 46.1 | 102 | 48 | 44.9 | 100 | 48
40 | 48.7 | 48 | 46.6 | 96 | 47 | 48.1 | 103 | 48 | 46.2 | 99 | 48 | 47.6 | 102 | 48 | 45.6 | 98 | 47
44 | 49.1 | 48 | 48.3 | 98 | 47 | 49.1 | 102 | 48 | 47.4 | 98 | 48 | 49.1 | 102 | 48 | 47.5 | 98 | 47
48 | 49.7 | 48 | 49.1 | 99 | 47 | 49.4 | 101 | 48 | 47.5 | 97 | 48 | 50.1 | 102 | 47 | 48.1 | 98 | 47
52 | 50.3 | 48 | 49.1 | 98 | 47 | 49.6 | 101 | 47 | 47.7 | 97 | 48 | 50.0 | 102 | 47 | 48.1 | 98 | 47
56 | 50.4 | 48 | 49.0 | 97 | 47 | 49.9 | 102 | 46 | 48.3 | 99 | 48 | 50.6 | 103 | 47 | 48.3 | 99 | 47
60 | 50.3 | 47 | 49.2 | 98 | 47 | 49.9 | 101 | 46 | 48.5 | 99 | 47 | 50.1 | 102 | 46 | 47.6 | 97 | 47
64 | 50.8 | 47 | 49.8 | 98 | 47 | 50.1 | 101 | 44 | 49.1 | 99 | 47 | 50.9 | 102 | 46 | 47.7 | 96 | 46
68 | 50.8 | 47 | 50.4 | 99 | 46 | 50.5 | 100 | 43 | 49.4 | 98 | 47 | 50.6 | 100 | 46 | 47.7 | 95 | 44
72 | 51.4 | 46 | 50.9 | 99 | 45 | 50.7 | 100 | 43 | 49.8 | 98 | 46 | 51.1 | 100 | 44 | 49.2 | 97 | 42
76 | 51.0 | 43 | 50.4 | 99 | 45 | 50.8 | 101 | 42 | 50.3 | 100 | 46 | 51.5 | 102 | 42 | 49.2 | 98 | 40
80 | 50.9 | 41 | 51.1 | 100 | 43 | 50.7 | 99 | 42 | 50.1 | 98 | 45 | 51.5 | 101 | 40 | 48.7 | 95 | 40
84 | 51.5 | 39 | 51.6 | 100 | 42 | 50.9 | 99 | 42 | 50.4 | 98 | 43 | 51.6 | 100 | 39 | 48.7 | 94 | 40
88 | 51.3 | 36 | 51.8 | 101 | 41 | 50.5 | 96 | 39 | 49.7 | 97 | 42 | 50.5 | 97 | 38 | 48.7 | 94 | 39
92 | 50.6 | 35 | 51.3 | 101 | 40 | 49.4 | 96 | 37 | 49.0 | 96 | 42 | 49.6 | 97 | 36 | 47.8 | 93 | 38
96 | 50.4 | 33 | 50.6 | 100 | 38 | 48.8 | 96 | 35 | 49.9 | 99 | 39 | 49.9 | 99 | 32 | 47.3 | 93 | 35
100 | 49.9 | 32 | 50.3 | 101 | 37 | 48.7 | 97 | 30 | 49.5 | 98 | 36 | 49.5 | 98 | 30 | 47.6 | 95 | 32
Mean for Weeks 1–104^c,d^ | 44.6 | | 44.2** | 99 | | 44.2 | 100 | | 43.3 | 98 | | 44.4 | 100 | | 42.7** | 97

Statistical significance for the untreated control group or a dosed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

** Statistically significant at p ≤ 0.01.

^a^ Weight (% of controls) is given as a percentage of the untreated control.

^b^ Weight (% of controls) is given as a percentage of the vehicle control.

^c^ Statistical analysis performed using repeated-measures mixed-effects ANOVA (trend) and the Dunnett-Hsu (pairwise) tests.

^d^ Trend analysis was also performed on the vehicle control group and on all exposed groups using a reduced 1-year data record of the mean body weights for postnatal day 50–386. No statistically significant findings were noted at p ≤ 0.05.

Figure 3

Growth Curves for Male and Female Mice in the Two-year Dermal Study of Triclosan

Growth curves are shown for (A) males and (B) females.

Table 4 Summary of Survival and Body Weights of Female Mice in the Two-year Dermal Study of Triclosan

Study Week^a^ | Untreated Control | | Vehicle Control | | | 1.25 mg/kg/day | | | 2.7 mg/kg/day | | | 5.8 mg/kg/day | | | 12.5 mg/kg/day
Study Week^a^ | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls)^a^ | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls)^b^ | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls)^b^ | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls)^b^ | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls)^b^ | No. of Survivors
1 | 19.7 | 48 | 19.5 | 99 | 48 | 19.6 | 101 | 48 | 19.6 | 101 | 48 | 19.4 | 100 | 47 | 19.8 | 101 | 48
4 | 23.1 | 48 | 23.2 | 101 | 48 | 23.5 | 101 | 48 | 23.3 | 100 | 48 | 23.1 | 99 | 47 | 23.4 | 101 | 48
8 | 25.8 | 48 | 26.2 | 102 | 48 | 26.3 | 100 | 48 | 26.2 | 100 | 48 | 25.9 | 99 | 47 | 25.8 | 98 | 48
12 | 29.1 | 48 | 29.2 | 100 | 48 | 29.3 | 100 | 48 | 29.2 | 100 | 48 | 29.2 | 100 | 47 | 28.4 | 97 | 48
16 | 31.7 | 48 | 32.1 | 101 | 48 | 32.1 | 100 | 48 | 31.9 | 99 | 48 | 31.4 | 98 | 47 | 30.2 | 94 | 48
20 | 33.2 | 48 | 33.9 | 102 | 48 | 33.9 | 100 | 48 | 33.6 | 99 | 48 | 33.0 | 98 | 47 | 31.7 | 94 | 48
24 | 36.8 | 48 | 36.6 | 99 | 48 | 36.3 | 99 | 48 | 36.1 | 99 | 48 | 35.4 | 97 | 47 | 34.5 | 94 | 48
28 | 39.3 | 48 | 39.0 | 99 | 48 | 38.4 | 98 | 48 | 38.4 | 98 | 48 | 37.8 | 97 | 47 | 36.8 | 94 | 48
32 | 42.3 | 48 | 41.1 | 97 | 48 | 40.7 | 99 | 48 | 40.3 | 98 | 48 | 39.2 | 95 | 47 | 38.1 | 93 | 48
36 | 44.6 | 48 | 42.3 | 95 | 48 | 42.3 | 100 | 47 | 41.5 | 98 | 48 | 40.1 | 95 | 47 | 39.8 | 94 | 48
40 | 45.9 | 48 | 43.8 | 95 | 48 | 44.1 | 101 | 47 | 43.3 | 99 | 48 | 42.2 | 96 | 47 | 41.1 | 94 | 48
44 | 47.8 | 48 | 46.3 | 97 | 48 | 46.0 | 99 | 47 | 45.4 | 98 | 48 | 44.2 | 95 | 47 | 42.8 | 92 | 48
48 | 49.3 | 48 | 47.4 | 96 | 48 | 46.9 | 99 | 47 | 46.0 | 97 | 48 | 45.2 | 96 | 47 | 43.9 | 93 | 48
52 | 49.7 | 48 | 48.4 | 97 | 47 | 47.4 | 98 | 47 | 46.7 | 97 | 48 | 45.9 | 96 | 47 | 43.9 | 92 | 48
56 | 49.9 | 48 | 48.4 | 97 | 47 | 48.1 | 99 | 47 | 47.0 | 98 | 48 | 46.3 | 97 | 47 | 44.7 | 93 | 48
60 | 49.2 | 48 | 48.6 | 99 | 47 | 48.4 | 100 | 47 | 47.0 | 97 | 48 | 46.8 | 97 | 46 | 44.8 | 93 | 48
64 | 50.0 | 48 | 49.5 | 99 | 47 | 48.9 | 99 | 47 | 48.0 | 97 | 47 | 48.2 | 97 | 46 | 45.4 | 92 | 48
68 | 50.4 | 46 | 50.1 | 99 | 47 | 49.8 | 99 | 47 | 48.2 | 96 | 47 | 48.7 | 97 | 45 | 46.4 | 93 | 47
72 | 50.6 | 45 | 51.5 | 102 | 47 | 49.9 | 97 | 46 | 49.0 | 95 | 46 | 49.7 | 97 | 43 | 47.2 | 92 | 46
76 | 51.4 | 44 | 50.8 | 99 | 47 | 49.9 | 98 | 42 | 49.1 | 97 | 44 | 49.3 | 97 | 43 | 47.3 | 93 | 45
80 | 50.5 | 44 | 51.4 | 102 | 46 | 49.4 | 96 | 42 | 49.0 | 95 | 44 | 48.9 | 95 | 42 | 47.9 | 93 | 44
84 | 50.3 | 42 | 51.7 | 103 | 45 | 50.0 | 97 | 40 | 49.6 | 96 | 44 | 49.9 | 97 | 40 | 47.7 | 92 | 44
88 | 50.6 | 41 | 51.6 | 102 | 41 | 49.8 | 97 | 39 | 49.1 | 95 | 43 | 49.1 | 95 | 40 | 47.4 | 92 | 43
92 | 49.7 | 40 | 51.0 | 103 | 39 | 48.8 | 96 | 37 | 48.1 | 94 | 41 | 48.0 | 94 | 40 | 47.7 | 94 | 40
96 | 48.6 | 38 | 49.7 | 102 | 38 | 46.9 | 94 | 33 | 46.8 | 94 | 34 | 48.2 | 97 | 39 | 46.9 | 94 | 39
100 | 47.7 | 34 | 48.8 | 102 | 36 | 46.9 | 96 | 30 | 45.6 | 93 | 32 | 47.1 | 97 | 37 | 46.1 | 94 | 37
Mean for Weeks 1–104^c,d^ | 42.6 | | 42.3*** | 99 | | 41.6 | 98 | | 41.1 | 97 | | 40.7 | 96 | | 39.4*** | 93

Statistical significance for the untreated control group or a dosed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

*** Statistically significant at p ≤ 0.001.

^a^ Weight (% of controls) is given as a percentage of the untreated control.

^b^ Weight (% of controls) is given as a percentage of the vehicle control.

^c^ Statistical analysis performed using mixed-effects ANOVA (trend) and the Dunnett-Hsu (pairwise) tests.

^d^ Trend analysis was also performed on the vehicle control group and on all exposed groups using a reduced 1-year data record of the mean body weights for postnatal day 50–386. Statistically significant findings were noted at p ≤ 0.001 for the trend and pairwise comparison in the 12.5 mg/kg/day group.

#### Histopathology

This section describes the statistically significant or biologically noteworthy changes in the incidence of neoplasms and/or nonneoplastic lesions of the liver, pancreas, and skin. The appropriate statistical comparison is to the vehicle control animals, which were subjected to the same daily stress of handling and dosing as the triclosan-dosed groups. Data from the untreated control animals are also reported.

Liver: In male mice, triclosan administration resulted in positive trends in the incidences of hepatocellular carcinoma and hepatocellular adenoma or carcinoma (combined), with the increase being significant in the ≥5.8 and ≥2.7 mg/kg/day groups, respectively, compared to the vehicle control group (Table 5). The incidence of hepatocellular carcinomas in the untreated control males was higher than that in the vehicle control males (Table 5). In female mice, there were no significant increases in the incidences of hepatocellular adenoma, hepatocellular carcinoma, or hepatocellular adenoma or carcinoma (combined). The multiplicity of hepatocellular neoplasms is presented in Table 5. No exposure-related nonneoplastic lesions were observed in the liver.

Table 5 Incidences of Neoplasms of the Liver in Male and Female Mice in the Two-year Dermal Study of Triclosan

| Untreated Control | Vehicle Control | 1.25 mg/kg/day | 2.7 mg/kg/day | 5.8 mg/kg/day | 12.5 mg/kg/day
n^a^ | 48 | 48 | 48 | 48 | 48 | 48
Male
Hepatocellular Adenoma, Multiple^b,c^ | 16 (33%) | 16 (33%) | 21 (44%) | 23 (48%) | 17 (35%) | 17 (35%)
Hepatocellular Adenoma (Includes Multiple)^d^
Overall rate^e^ | 26/48 (54%) | 25/48 (52%) | 30/48 (63%) | 34/48 (71%) | 31/48 (65%) | 26/48 (54%)
Adjusted rate^f^ | 61.1% | 56.8% | 71.2% | 75.1% | 72.4% | 59.2%
Terminal rate^g^ | 20/31 (65%) | 21/35 (60%) | 23/30 (77%) | 27/34 (79%) | 23/28 (82%) | 17/31 (55%)
First incidence (days) | 513 | 478 | 597 | 407 | 492 | 282
Poly-3 test^h^ | – | p = 0.328N | p = 0.113 | p = 0.047 | p = 0.088 | p = 0.495
Poly-3 test (controls)^i^ | – | p = 0.423N | – | – | – | –
Hepatocellular Carcinoma, Multiple | 3 (6%) | 1 (2%) | 6 (13%) | 4 (8%) | 6 (13%) | 6 (13%)
Hepatocellular Carcinoma (Includes Multiple)^j^
Overall rate | 27/48 (56%) | 15/48 (31%) | 17/48 (35%) | 20/48 (42%) | 25/48 (52%) | 27/48 (56%)
Adjusted rate | 57% | 32.5% | 38.8% | 43.0% | 54.4% | 59.5%
Terminal rate | 12/31 (39%) | 7/35 (20%) | 8/30 (27%) | 11/34 (32%) | 11/28 (39%) | 14/31 (45%)
First incidence (days) | 417 | 478 | 468 | 407 | 336 | 462
Poly-3 test | – | p = 0.003 | p = 0.343 | p = 0.204 | p = 0.025 | p = 0.007
Poly-3 test (controls) | – | p = 0.013N | – | – | – | –
Hepatocellular Adenoma or Carcinoma (Combined)^k^
Overall rate | 41/48 (85%) | 31/48 (65%) | 35/48 (73%) | 40/48 (83%) | 42/48 (88%) | 40/48 (83%)
Adjusted rate | 85.4% | 67.1% | 78.8% | 84.9% | 89.0% | 84.7%
Terminal rate | 24/31 (77%) | 22/35 (63%) | 23/30 (77%) | 28/34 (82%) | 24/28 (86%) | 24/31 (77%)
First incidence (days) | 417 | 478 | 468 | 407 | 336 | 282
Poly-3 test | – | p = 0.044 | p = 0.150 | p = 0.034 | p = 0.008 | p = 0.036
Poly-3 test (controls) | – | p = 0.029N | – | – | – | –
Female
Hepatocellular Adenoma, Multiple | 11 (23%) | 5 (10%) | 5 (10%) | 8 (17%) | 9 (19%) | 5 (10%)
Hepatocellular Adenoma (Includes Multiple)^l^
Overall rate | 22/48 (46%) | 17/48 (35%) | 13/48 (27%) | 17/48 (35%) | 18/48 (38%) | 17/48 (35%)
Adjusted rate | 49.2% | 38.3% | 31.1% | 39.4% | 41.3% | 37.8%
Terminal rate | 18/33 (55%) | 13/35 (37%) | 9/29 (31%) | 13/31 (42%) | 13/37 (35%) | 12/35 (34%)
First incidence (days) | 483 | 590 | 533 | 664 | 580 | 475
Poly-3 test | – | p = 0.440 | p = 0.318N | p = 0.545 | p = 0.470 | p = 0.566N
Poly-3 test (controls) | – | p = 0.203N | – | – | – | –
Hepatocellular Carcinoma, Multiple | 2 (4%) | 0 (0%) | 0 (0%) | 1 (2%) | 2 (4%) | 0 (0%)
Hepatocellular Carcinoma (Includes Multiple)^m^
Overall rate | 12/48 (25%) | 10/48 (21%) | 6/48 (13%) | 9/48 (19%) | 8/48 (17%) | 7/48 (15%)
Adjusted rate | 26.7% | 22.6% | 14.4% | 20.6% | 18.2% | 15.7%
Terminal rate | 7/33 (21%) | 6/35 (17%) | 2/29 (7%) | 6/31 (19%) | 4/37 (11%) | 4/35 (11%)
First incidence (days) | 477 | 596 | 533 | 535 | 484 | 475
Poly-3 test | – | p = 0.330N | p = 0.241N | p = 0.514N | p = 0.405N | p = 0.290N
Poly-3 test (controls) | – | p = 0.418N | – | – | – | –
Hepatocellular Adenoma or Carcinoma (Combined)^n^
Overall rate | 25/48 (52%) | 22/48 (46%) | 18/48 (38%) | 21/48 (44%) | 21/48 (44%) | 20/48 (42%)
Adjusted rate | 54.6% | 48.8% | 42.3% | 47.7% | 46.8% | 44.4%
Terminal rate | 18/33 (55%) | 16/35 (46%) | 11/29 (38%) | 15/31 (48%) | 14/37 (38%) | 15/35 (43%)
First incidence (days) | 477 | 590 | 533 | 535 | 484 | 475
Poly-3 test | – | p = 0.450N | p = 0.346N | p = 0.541N | p = 0.506N | p = 0.418N
Poly-3 test (controls) | – | p = 0.366N | – | – | – | –

^a^ Number of animals with tissue examined microscopically.

^b^ Number of animals with lesion.

^c^ No statistical analyses were performed on multiplicity data.

^d^ Historical control incidence for all routes of 2-year studies (mean ± standard deviation): 398/789 (50.04 ± 9.88%); range: 34% to 70%.

^e^ Number of animals with neoplasm/number of animals necropsied.

^f^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^g^ Observed incidence at study termination.

^h^ Beneath the vehicle control incidence is the p value associated with the trend test. Beneath the dosed group incidence is the p value corresponding to pairwise comparisons between the vehicle control group and that dosed group. The Poly-3 test accounts for differential mortality in animals that do not reach study termination. A negative trend or a lower incidence in a dose group is indicated by N.

^i^ Beneath the vehicle control incidence is the p value corresponding to a pairwise comparison between the vehicle control group and the untreated control group. A lower incidence in the vehicle control group is indicated by N.

^j^ Historical control incidence: 201/789 (25.16% ± 9.06%); range: 10% to 42%.

^k^ Historical control incidence: 513/789 (64.5% ± 10.59%); range: 46% to 80%.

^l^ Historical control incidence: 150/839 (17.71% ± 7.01%); range: 6% to 28%.

^m^ Historical control incidence: 71/839 (8.44% ± 18%); range: 2% to 20%.

^n^ Historical control incidence: 203/849 (23.88% ± 8.96%); range: 8% to 40%.

Pancreas: Female mice dosed with triclosan had a positive trend in the incidence of pancreatic islet adenoma; however, the increased incidence did not reach statistical significance in pairwise comparisons in dosed groups compared to the vehicle control group (Table 6). Neither pancreatic islet hyperplasia nor adenoma was observed in untreated female mice. Pancreatic islet carcinoma was observed in one female in both the untreated and vehicle control groups.

Table 6 Incidences of Neoplasms and Nonneoplastic Lesions of the Pancreas in Female Mice in the Two-year Dermal Study of Triclosan

| Untreated Control | Vehicle Control | 1.25 mg/kg/day | 2.7 mg/kg/day | 5.8 mg/kg/day | 12.5 mg/kg/day
n^a^ | 48 | 48 | 48 | 48 | 48 | 48
Islets, Hyperplasia^b^ | 0 | 1 (2.0)^c^ | 0 | 1 (2.0) | 0 | 1 (2.0)
Islets, Adenoma^d^
Overall rate^e^ | 0/48 (0%) | 1/48 (2%) | 0/48 (0%) | 0/48 (0%) | 0/48 (0%) | 3/48 (6%)
Adjusted rate^f^ | 0.0% | 2.3% | 0.0% | 0.0% | 0.0% | 6.9%
Terminal rate^g^ | 0/33 (0.0%) | 0/35 (0%) | 0/29 (0%) | 0/31 (0%) | 0/37 (0%) | 2/35 (6%)
First incidence (days)^h^ | – | 590 | – | – | – | 663
Poly-3 test^i^ | – | p = 0.033^j^ | p = 0.515N | p = 0.505N | p = 0.507N | p = 0.305
Islets, Carcinoma^k^ | 1 | 1 | 0 | 0 | 0 | 0
Islets, Adenoma or Carcinoma (Combined)^l^
Overall rate | 1/48 (2%) | 2/48 (4%) | 0/48 (0%) | 0/48 (0%) | 0/48 (0%) | 3/48 (6%)
Adjusted rate | 2.4% | 4.5% | 0.0% | 0.0% | 0.0% | 6.9%
Terminal rate | 1/33 (3%) | 0/35 (0%) | 0/29 (0%) | 0/31 (0%) | 0/37 (0%) | 2/35 (6%)
First incidence (days) | 726 | 590 | – | – | – | 663
Poly-3 test | – | p = 0.121 | p = 0.257N | p = 0.245N | p = 0.247N | p = 0.495
Poly-3 test (controls)^m^ | – | p = 0.511 | – | – | – | –

^a^ Number of animals with tissue examined microscopically.

^b^ Number of animals with lesion.

^c^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

^d^ Historical control incidence for all routes of 2-year studies (mean ± standard deviation): 3/832 (0.38% ± 0.81%); range: 0% to 2%.

^e^ Number of animals with neoplasm/number of animals necropsied.

^f^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^g^ Observed incidence at terminal euthanasia.

^h^ Not applicable if there were no neoplasms in group.

^i^ Beneath the vehicle control incidence is the p value associated with the trend test. Beneath the dosed group incidence is the p value corresponding to pairwise comparisons between the vehicle control group and that dosed group. The Poly-3 test accounts for differential mortality in animals that do not reach study termination. A negative trend or a lower incidence in a dose group is indicated by N.

^j^ A Poly-3 analysis was conducted only if the incidence in one of the groups was ≥4% and was therefore not run to compare the vehicle control group with the untreated control group.

^k^ Historical control incidence: 1/832 (0.07% ± 0.29%); range: 0% to 1%.

^l^ Historical control incidence: 4/832 (0.45% ± 0.82%); range: 0% to 2%.

^m^ Beneath the vehicle control incidence is the p value corresponding to a pairwise comparison between the vehicle control group and the untreated control group.

Pancreatic islet hyperplasia was characterized by an increase in the size of islets and islet cell numbers featuring a multifocal to diffuse distribution. The outline of hyperplastic islets was sometimes irregular with no compression of the surrounding acinar tissue. Islet cells were frequently hypertrophic but uniform. In contrast, islet cell adenomas were larger and well-circumscribed with compression of the peripheral tissue. Cellular growth patterns within the neoplasm ranged from sheets to nests or ribbons and pale staining.

Skin: Dose-related minimal to mild skin lesions were observed at the site of application in male and female mice. Male mice dosed with triclosan had a positive trend in the incidences of hyperplasia, suppurative inflammation, and ulceration of the epidermis at the site of application (Table 7). The incidence of epidermal hyperplasia became significant at 2.7 mg/kg/day and was present in approximately 90% of male mice at 12.5 mg/kg/day. The incidences of epidermal suppurative inflammation and ulceration were significantly increased at 12.5 mg/kg/day. Female mice dosed with triclosan had a positive trend in the incidence of hyperplasia of the epidermis at the site of application (Table 7). The incidence of epidermal hyperplasia became significant at 1.25 mg/kg/day and was present in approximately 80% of female mice at 12.5 mg/kg/day.

Table 7 Incidences of Nonneoplastic Lesions of the Skin at the Site of Application in Male and Female Mice in the Two-year Dermal Study of Triclosan

| Untreated Control | Vehicle Control | 1.25 mg/kg/day | 2.7 mg/kg/day | 5.8 mg/kg/day | 12.5 mg/kg/day
n^a^ | 48 | 48 | 48 | 48 | 48 | 48
Male
Epidermis, Hyperplasia^b^ | 2 (2.0)^c^ | 1** (1.0) | 3 (2.3) | 20** (1.2) | 17** (1.2) | 43** (1.4)
Epidermis, Inflammation, Suppurative | 2 (2.5) | 0** | 3 (2.7) | 2 (2.0) | 4 (1.5) | 9** (2.0)
Epidermis, Ulcer | 2 (2.0) | 0* | 2 (3.0) | 1 (3.0) | 2 (1.5) | 5* (2.4)
Female
Epidermis, Hyperplasia | 1 (1.0) | 0** | 5* (1.8) | 7** (1.1) | 10** (1.2) | 39** (1.2)

Statistical significance for a dosed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05 by the Poly-3 test; **p ≤ 0.01.

^a^ Number of animals examined microscopically.

^b^ Number of animals with lesion.

^c^ Average severity grade of observed lesion in affected animals: 1 = minimal; 2 = mild; 3 = moderate; 4 = marked.

Epidermal hyperplasia was characterized by a thickening of the squamous epithelium due to increased layers of nucleated cells in the epidermis, with one or two cell layers considered as normal, three or four layers as minimal hyperplasia, five or six layers as mild hyperplasia, seven or eight layers as moderate hyperplasia, and more than eight layers as marked hyperplasia. Epidermal suppurative inflammation exhibited a predominant neutrophilic infiltrate. Epidermal ulceration was defined as complete loss of the epidermis with an overlying serocellular crust.

Other tissues: Male mice had positive trends in the incidences of histocyte infiltration of the lung and lymphoid tissue hyperplasia of the small intestine (Appendix E). Significantly increased incidences of lymphoid hyperplasia of the mandibular lymph node and lymphocyte infiltration of the urinary bladder were observed at 5.8 mg/kg/day. Suppurative inflammation of the preputial gland was also observed at 1.25 mg/kg/day. There were no differences in nonneoplastic lesions between the vehicle control group and the untreated control group. Female mice also had positive trends in the incidences of angiectasis and pars distalis hyperplasia of the pituitary gland, with the incidence of angiectasis becoming significant at 12.5 mg/kg/day. Pancreatic ductal dilatation also had a positive trend. Significantly increased incidences of lymphocytic infiltration of the Harderian gland and duct dilatation of the clitoral gland were observed at 12.5 mg/kg/day and 1.25 mg/kg/day, respectively. Except for lymphocytic infiltration of the Harderian gland, there were no differences in nonneoplastic lesions between the vehicle control group and the untreated control group (Appendix E).

## Benchmark Dose Analysis

Benchmark dose (BMD) modeling was conducted on neoplasms (hepatocellular carcinoma in male mice and pancreatic islet adenoma in female mice) and nonneoplastic lesions (hyperplasia, suppurative inflammation, and ulceration of the epidermis in male mice and hyperplasia of the epidermis in female mice) (Table 8). Additional nonneoplastic lesions used for BMD modeling are presented in Appendix D. The 95% lower bound on the BMD corresponding to a 10% extra risk (BMDL_10_) for hepatocellular carcinoma in male mice ranged from 1.1 to 2.4 mg/kg/day, whereas the BMDL_10_ for pancreatic islet adenoma in female mice ranged from 11.7 to 12.3 mg/kg/day. In both male and female mice, the most sensitive nonneoplastic endpoint was epidermal hyperplasia. In male mice, the BMD calculations failed when using the entire epidermal hyperplasia data set. When the calculations were repeated without the 2.7 mg/kg/day group, the BMDL_10_ ranged from 1.6 to 2.8 mg/kg/day; when the 5.8 mg/kg/day group was eliminated, the comparable values were 0.88–0.93 mg/kg/day. In female mice, the BMDL_10_ for epidermal hyperplasia ranged from 1.5 to 3.0 mg/kg/day. Higher values were obtained for epidermal suppurative inflammation (3.1–7.6 mg/kg/day) and epidermal ulceration (6.6–9.7 mg/kg/day) in male mice.

Table 8 Benchmark Dose Modeling Results for Select Neoplasms and Nonneoplastic Lesions in Male and Female Mice in the Two-year Dermal Study of Triclosan

Neoplasm or Nonneoplastic Lesion | BMDL_10_ (mg/kg/day)
Male
Neoplasm
Hepatocellular carcinoma | 1.1–2.4
Nonneoplastic Lesions
Epidermis, hyperplasia^a^ | 1.6–2.8
Epidermis, hyperplasia^b^ | 0.88–0.93
Epidermis, inflammation, suppurative | 3.1–7.6
Epidermis, ulcer | 6.6–9.7
Female
Neoplasm
Pancreas, islets, adenoma | 11.7–12.3
Nonneoplastic Lesion
Epidermis, hyperplasia | 1.5–3.0

BMDL_10_ = 95% lower bound on the benchmark dose corresponding to a 10% extra risk of the specified adverse effect over that observed in the vehicle control group. Benchmark calculations were conducted using gamma, logistic, log-logistic, log-probit, multistage, probit, and Weibull models to fit the incidences of neoplasms and nonneoplastic lesions and the doses of triclosan administered dermally. The values shown are the range of BMDLs calculated for a specific neoplasm or nonneoplastic lesion across the various models used.

^a^ Calculations were run using all dosed groups except the 2.7 mg/kg/day group.

^b^ Calculations were run using all dosed groups except the 5.8 mg/kg/day group.