# Materials and Methods

## Procurement and Characterization

### Triclosan

Triclosan was obtained from Alfa Aesar (Ward Hill, MA) in a single lot (5001A29X). Identity, purity, and stability analyses were conducted by the study laboratory at the U.S. Food and Drug Administration’s National Center for Toxicological Research (NCTR, Jefferson, AR). Reports on analyses performed in support of the triclosan studies are on file at the National Institute of Environmental Health Sciences.

The identity of the test lot was evaluated using ^1^H nuclear magnetic resonance (NMR) spectroscopy. The ^1^H NMR spectrum was consistent with the structure of triclosan and identical to that of the reference standard (lot 1412854V, Sigma Aldrich, St. Louis, MO) (Appendix A). No resonances due to contaminants were present in the spectrum except those produced by water and solvent. The identity of lot 5001A29X was further confirmed using mass spectrometry (MS) after separation by high-performance liquid chromatography (HPLC) with diode array detection (PDA) (Table A-1). The MS spectrum was consistent with the structure of triclosan, which confirmed that the test lot corresponded to triclosan.

Purity evaluation was conducted by HPLC/PDA using a 1.0 mg/mL sample of the test lot dissolved in methanol (Table A-1). No impurities were identified. The overall purity of lot 5001A29X was estimated to be 99.9% by comparing the peak area with the reference standard, which was consistent with the 99.0% purity indicated by the manufacturer. The ^1^H NMR analysis of the test article was consistent with this purity determination. Repeated purity evaluation conducted at the end of the study confirmed a purity of 99.9%.

The test article was received in amber jars and stored at room temperature.

### Ethanol

The 95% ethanol dose vehicle was obtained from Decon Laboratories (King of Prussia, PA) in a single lot (2801G). The identity of ethanol was confirmed using ^1^H NMR spectroscopy. The NMR spectrum was consistent with the structure of ethanol, and there was no evidence of contamination by other proton-containing compounds (Appendix A).

Purity evaluation of lot 2801G was conducted by the study laboratory using HPLC/PDA (Table A-1). The chromatograms did not show any ultraviolet chromophore-containing components above background, confirming a purity consistent with the 95% purity specified by the vendor. Batches of the ethanol dose vehicle were evaluated for the presence of triclosan before and after the study, and no triclosan was detected.

The ethanol dose vehicle was received in amber glass containers and stored at room temperature.

## Preparation and Analysis of Dose Formulations

Dose formulations of triclosan (lot 5001A29X) in 95% ethanol were prepared by Priority One Services (Alexandria, VA) following protocols outlined in Appendix A. Dose formulations were prepared at 1.25, 2.7, 5.8, and 12.5 mg/L (25 preparations; September 2013–August 2015) and were refrigerated, protected from light, and used within approximately 1 month of mixing.

Stability studies of the dose formulations stored at room (25°C) or refrigerated (2°C–8°C) temperatures were conducted using HPLC/PDA (Table A-1). The lowest (1.25 mg/mL) and highest (12.5 mg/mL) dose formulations were evaluated after 8 weeks at refrigerated temperatures or 4 weeks at room temperature. Stability for up to 56 days under refrigerated temperatures was confirmed. Additionally, the dose formulations were found to be homogeneous.

Analyses of preadministration dose formulations were conducted by the study laboratory using HPLC/PDA (Table A-1). All dose formulations were within 10% of the target concentrations.

## Analysis of Triclosan in Experimental Background Materials

The animal feed (NTP-2000 Irradiated Rodent Diet) and drinking water (Millipore-filtered drinking water) were analyzed for the presence of background triclosan using ultra-performance liquid chromatography (UPLC) with MS (Table A-1). Animal feed samples were ground to a powder and extracted with acetonitrile. The acetonitrile supernatant was assayed by UPLC-MS and compared with feed samples spiked at 1 ppm triclosan. Although a prominent triclosan peak was observed in the spiked samples, the peak was not detectable in the unspiked samples, indicating that any possible background levels of triclosan in the feed were not present at or above 1 ppm. Additionally, peak areas observed for triclosan in the three drinking water samples were negligible in comparison with water samples spiked at 1 ppm triclosan, indicating that the drinking water triclosan levels were not present at or above 1 ppm.

## Animal Source

Male and female B6C3F1/N mice were obtained from the National Toxicology Program (NTP) colony maintained by Taconic Biosciences, Inc. (Germantown, NY).

## Animal Welfare

Animal care and use are in accordance with the Public Health Service Policy on Humane Care and Use of Animals. All animal studies were conducted in an animal facility accredited by AAALAC International. Studies were approved by the NCTR (Jefferson, AR) Animal Care and Use Committee and conducted in accordance with all relevant National Institutes of Health and NTP animal care and use policies and applicable federal, state, and local regulations and guidelines.

## Two-year Study

### Dose Selection Rationale

To formulate a scientific basis for the dose selection for the 2-year dermal carcinogenicity bioassay, a dermal subchronic study was conducted.^4^ Body weight changes and increases in the incidences of epidermal hyperplasia and parakeratosis at the site of application in the 27 mg triclosan/kg body weight/day (mg/kg/day) groups informed the selection of 12.5 mg/kg/day triclosan in ethanol as the high dose for male and female B6C3F1/N mice. The lowest dose selected was 10-fold lower than the highest dose, and the intermediate doses were equally spaced between the highest and lowest doses, based on a 10^(1/3)^ dose spacing. Specifically, male and female B6C3F1/N mice were dermally administered 0, 1.25, 2.7, 5.8, or 12.5 mg/kg/day triclosan in 95% ethanol, 7 days per week for 2 years.

### Study Design for Mice

Male and female B6C3F1/N mice were 3 weeks old upon receipt and were quarantined for 3 weeks before study start. At 5 weeks of age, mice were randomly assigned to one of six dose groups (n = 48 mice/sex/dose group). Randomization was stratified by body weight that produced similar group mean body weights using SAS software, Version 9.2 (Cary, NC). Starting at 6 weeks of age, mice were left untreated or dermally administered 0 (vehicle control group), 1.25, 2.7, 5.8, or 12.5 mg/kg/day triclosan for 2 years.

Approximately 24 hours before the first dermal administration of triclosan, the fur of each mouse was closely clipped on the dorsal surface from the shoulder region to the lumbar region using a Wahl Pocket Pro compact trimmer (Shelton, CT) with a size 40 blade. The clippers were battery operated and disposable; the blades were not changed. New clippers were used weekly (at the beginning of a clipping session) or as needed should the blade appear too dull during clipping. There were no instances when the clippers became hot. The mice groups were clipped in the following order: vehicle control, low dose, middle dose, and high dose. The untreated control animals were clipped after all other activities (i.e., weighing, clipping, and dosing animals; clinical observations; and cage changes) were completed for the vehicle control and dosed animals. Gloves were changed and the workstation was cleaned with disinfectant detergent and wiped with a 70% ethanol solution before clipping the untreated control mice. A separate set of clippers was used for the untreated control animals. The clipped area was rinsed with water, dried, and examined for nicks or breaks in the skin. The rinsing procedure was performed every time the animal was clipped. The site of application was re-clipped approximately once per week or as needed during the study. For animals with sores at the application site, care was taken to avoid clipping the fur in the areas containing sores to prevent further irritation to the area. Each animal in all six dose groups was clipped in this manner for the duration of the study. Any animal with abrasions or lesions in the clipped area was evaluated for possible exclusion from the study. No procedures were implemented to prevent incidental ingestion due to normal grooming behavior; however, animals were housed individually, and dorsal application was utilized to limit oral exposure. Elizabethan collars were not used due to the potential stress they would cause to the mice during the 2-year study.

All doses were administered in ethanol, at a dose volume of 1.0 mL/kg body weight; vehicle control animals received ethanol only and the untreated control group did not receive any dermal application of vehicle or test article. The animals were dosed in the following order: vehicle control, low dose, middle dose, and high dose (i.e., 0, 1.25, 2.7, 5.8, and 12.5 mg/kg/day). Dosing was conducted with a Hamilton Microlab 500 series pump, equipped with a Concord push-button hand pipettor/probe dispenser. The animals were placed on a grid, held by the base of their tails for dosing, and returned to their cages approximately 1 minute after the completion of dosing. The surface of the grid was cleaned if a dose was spilled as well as at the end of all dosing for the day. Gloves were changed between dose groups or more often if necessary. Dosing was completed for each mouse within 3 hours of the dosing time on the previous day. Untreated control animals were only handled while changing cages, clipping fur, weighing the animals, and performing clinical observations. The activities for untreated control animals were performed last, and gloves were changed before these animals were handled.

Twenty-eight male and 28 female mice were randomly selected for parasite evaluation and gross observation of disease. The health of the mice was monitored during the study as described in Appendix C. Additional animals were evaluated for disease screening prior to quarantine release; however, data are not included here. All test results from quarantine and sentinel evaluations were negative.

Mice were housed individually. Feed and water were available ad libitum. Cages were changed twice weekly and rotated every 2 weeks. Racks were changed and rotated every 2 weeks. Further details of animal maintenance are given in Table 1. Information on feed composition and contaminants is given in Appendix B.

Table 1 Experimental Design and Materials and Methods in the Two-year Dermal Study of Triclosan

Mice
Study Laboratory
National Center for Toxicological Research (Jefferson, AR)
Strain and Species
B6C3F1/N
Animal Source
Taconic Biosciences, Inc. (Germantown, NY)
Time Held Before Study
~3 weeks
Average Age When Study Began
6 weeks
Dates of First Dose
September 11–October 2, 2013
Duration of Dosing
2 years
Dates of Last Dose
September 6–29, 2015
Necropsy Dates
September 7–30, 2015
Average Age at Necropsy
2 years
Size of Study Groups
48/sex
Method of Distribution
Animals were distributed randomly into groups of approximately equal initial mean body weights
Animals per Cage
1
Method of Animal Identification
Cage card and tail tattoo
Diet
Irradiated NTP-2000 meal feed (Zeigler Brothers, Inc., Gardners, PA), available ad libitum, changed weekly
Water
Millipore-filtered drinking water, available ad libitum
Cages
Standard National Center for Toxicological Research polycarbonate filtered bonnets cages (Allentown, Inc., Allentown, NJ), changed twice weekly, rotated every 2 weeks. Filtered bonnets changed every 2 weeks.
Bedding
Beta chip bedding (Northeastern Products Corp., Warrensburg, NY), changed with cage changes
Racks
Metal animal cage racks (Allentown, Inc., Allentown, NJ), rotated and changed every 2 weeks
Animal Room Environment
Temperature: 60°F–78.8°F Relative humidity: 30%–90% Room fluorescent light: 12 hours/day Room air changes: 10–15/hour
Doses
Untreated, 0 (vehicle control group), 1.25, 2.7, 5.8, or 12.5 mg/kg/day in ethanol; 1 mL/kg dosing volume
Type and Frequency of Observation
Observed twice daily. Weighed before dermal administration on day 1, weekly thereafter, and at study termination. Clinical observations were recorded weekly. Abnormal observations, including skin lesions, were recorded daily. Digital images of the site of application were taken monthly until the occurrence of a skin neoplasm, at which time digital images were taken weekly.
Method of Euthanasia
Carbon dioxide
Necropsy
Necropsies were performed on all animals.
Histopathology
Complete histopathology was performed on all mice. In addition to gross lesions and tissue masses, the following tissues were examined: adrenal cortex, adrenal medulla, blood vessel, bone marrow, brain (brain stem, cerebellum, and cerebrum), clitoral gland, epididymis, esophagus, eye, femur, gallbladder, Harderian gland, heart, large intestine (cecum, colon, and rectum), small intestine (duodenum, jejunum, and ileum), kidney, liver, lung, lymph nodes (mandibular and mesenteric), mammary gland with adjacent skin, nose, ovary, pancreas, pancreatic islets, parathyroid gland, pituitary gland, preputial gland, prostate, salivary glands, seminal vesicle, skin (control and site of application), spleen, stomach (forestomach and glandular), testes, thymus, thyroid gland, trachea, urinary bladder, and uterus.

### Clinical Examinations and Pathology

In the 2-year study in mice, animals were observed twice daily for signs of morbidity and moribundity and were weighed before dermal administration of triclosan on day 1, weekly thereafter, and at study termination. Clinical observations were recorded weekly. Abnormal observations, including skin lesions, were recorded daily. Digital images of the site of application were taken monthly until the occurrence of a skin neoplasm, at which time digital images were taken weekly.

Complete necropsies and microscopic examinations were performed on all mice. At necropsy, all organs and tissues were examined for grossly visible lesions, and all major tissues were fixed and preserved in 10% neutral buffered formalin except for eyes and testes, which were first fixed in modified Davidson’s solution. Tissues were processed and trimmed, embedded in infiltrating media (Formula R^®^), sectioned at a thickness of approximately 5 μm, and stained with hematoxylin and eosin (H&E) for microscopic examination. For all paired organs (e.g., adrenal gland, kidney, ovary), samples from each organ were examined. Tissues examined microscopically are listed in Table 1.

Microscopic evaluations were completed by the study laboratory pathologist, and the pathology data were entered into the Toxicology Data Management System. The report, slides, paraffin blocks, residual wet tissues, and pathology data were sent to the NTP Archives for inventory, slide/block match, wet tissue audit, and storage. The slides, individual animal data records, and pathology tables were evaluated by a quality assessment (QA) pathologist at a pathology laboratory independent of the study laboratory. The individual animal records and tables were compared for accuracy, the slide and tissue counts were verified, and the histotechnique was evaluated. A QA pathologist evaluated slides from all neoplasms and all potential target organs, which included the skin (site of application) and liver.

The QA report and the reviewed slides were submitted to the Pathology Working Group (PWG) coordinator, who reviewed the selected tissues and addressed any inconsistencies in the diagnoses made by the laboratory and QA pathologists. Representative histopathology slides containing examples of lesions related to chemical administration, examples of disagreements in diagnoses between the laboratory and QA pathologists, or lesions of general interest were presented by the coordinator to the PWG for review. The PWG consisted of the QA pathologist and other pathologists experienced in rodent toxicologic pathology. This group examined the tissues without any knowledge of dose groups. When the PWG consensus diagnosis differed from that of the laboratory pathologist, the diagnosis was changed. Final diagnoses for reviewed lesions represent a consensus between the laboratory pathologist, reviewing pathologist(s), and the PWG. Details of these review procedures have been described, in part, by Maronpot and Boorman^9^ and Boorman et al.^10^ For subsequent analyses of the pathology data, the decision of whether to evaluate the diagnosed lesions for each tissue type separately or combined was based generally on the guidelines of Brix et al.^11^

### Benchmark Dose Analysis

Benchmark doses (BMD) and the lower 95% confidence limits (BMDL) were calculated using U.S. Environmental Protection Agency Benchmark Dose Software (version 2.4.0.70; https://www.epa.gov/bmds). The calculations were conducted using gamma, logistic, log-logistic, log-probit, multistage, probit, and Weibull models to fit the incidences of neoplasms and nonneoplastic lesions and the doses of triclosan administered dermally. The BMD_10_ and BMDL_10_ were defined as the dose that caused a 10% excess risk of the specified adverse effect over that observed in the vehicle control group and as the 95% lower bound on the BMD corresponding to a 10% extra risk, respectively.

## Statistical Methods

### Survival Analyses

The probability of survival was estimated by the product-limit procedure of Kaplan and Meier^12^ and is presented graphically. Animals surviving to the end of the observation period are treated as censored observations, as are animals dying from unnatural causes within the observation period. Animals dying from natural causes are included in analyses and are treated as uncensored observations. For the 2-year mouse study, dose-related trends are identified with Tarone’s life-table test,^13^ and pairwise dose-related effects are assessed using Cox’s method.^14^ All reported p values for the survival analyses are two-sided.

### Calculation of Incidence

The incidences of neoplasms or nonneoplastic lesions are presented as the numbers of animals bearing such lesions at a specific anatomic site. For calculation of incidence rates, the denominator for most neoplasms and all nonneoplastic lesions is the number of animals for which the site was examined microscopically. When macroscopic examination was required to detect neoplasms in certain tissues (e.g., mesentery, pleura, peripheral nerve, skeletal muscle, tongue, tooth, and Zymbal’s gland) before microscopic evaluation, however, the denominator consists of the number of animals that had a gross abnormality. When neoplasms had multiple potential sites of occurrence (e.g., leukemia or lymphoma), the denominator consists of the number of animals on which a necropsy was performed. Additional study data also give the survival-adjusted neoplasm rate for each group and each site-specific neoplasm. This survival-adjusted rate (based on the Poly-3 method described below) accounts for differential mortality by assigning a reduced risk of neoplasm, proportional to the third power of the fraction of time on study, only to site-specific, lesion-free animals that do not reach terminal euthanasia.

### Analysis of Neoplasm and Nonneoplastic Lesion Incidence

Statistical analyses of neoplasm and nonneoplastic lesion incidence considered two features of the data. Some animals did not survive the entire 2 years of the study, so survival differences between groups had to be considered.

The Poly-k test^15-17^ was used to assess neoplasm and nonneoplastic lesion prevalence. This test is a survival-adjusted quantal-response procedure that modifies the Cochran-Armitage linear trend test to account for survival differences. More specifically, this method modifies the denominator in the quantal estimate of lesion incidence to approximate more closely the total number of animal years at risk. For analysis of a given site, each animal is assigned a risk weight. This value is 1 if the animal had a lesion at that site or if it survived until terminal euthanasia; if the animal died before terminal euthanasia and did not have a lesion at that site, its risk weight is the fraction of the entire study time that it survived, raised to the kth power.

This method yields a lesion prevalence rate that depends only on the choice of a shape parameter for a Weibull hazard function describing cumulative lesion incidence over time.^15^ Unless otherwise specified, a value of k = 3 was used in the analysis of site-specific lesions. This value was recommended by Bailer and Portier^15^ after an evaluation of neoplasm onset time distributions for a variety of site-specific neoplasms in control Fischer 344 rats and B6C3F1 mice.^18^ Bailer and Portier^15^ showed that the Poly-3 test gave valid results if the true value of k was anywhere in the range from 1 to 5. A further advantage of the Poly-3 method is that it does not require lesion lethality assumptions. Variation introduced by the use of risk weights, which reflect differential mortality, was accommodated by adjusting the variance of the Poly-3 statistic as recommended by Bieler and Williams.^19^ Poly-3 tests used the continuity correction described by Nam.^20^

Tests of significance included pairwise comparisons of each dosed group with the vehicle control group, a pairwise comparison of the vehicle control group with the untreated control group, and a test for an overall dose-related trend. Continuity-corrected Poly-3 tests were used in the analysis of lesion incidence and reported p values are one-sided. The significance of a lower incidence or negative trend in lesions is approximated as 1−p with the letter N added (e.g., p = 0.99 is presented as p = 0.01N).

### Analysis of Continuous Variables

Each animal was weighed weekly starting at approximately PND 48; however, animals were not weighed at precisely the same time point relative to birth. Therefore, prior to analysis, locally estimated scatterplot smoothing (LOESS) was performed on the body weight data to rasterize to a set of common time points and reduce their number. The statistical model for the analysis of body weight was a repeated-measures, mixed-effects analysis of variance (ANOVA) model.^21^ A heterogeneous autoregressive covariance structure was used to account for body weight correlation across times within an animal and for the increasing variability in body weight as the body weights get larger. Comparisons to the vehicle control group were corrected using the Dunnett-Hsu method.^22^ To address considerable variability in body weights in the second year of the study and to consider any bias introduced during this time, an ANOVA was run on the full 2-year data record and also on a reduced 1-year data record (PND 50–386), during which minimal animal loss and body weight variations were observed.

### Historical Control Data

The concurrent vehicle control group is the most valid comparison to the dosed groups and is the only control group analyzed statistically in NTP bioassays. Historical control data are often helpful in interpreting potential dose-related effects, however, particularly for uncommon or rare neoplasm types. For meaningful comparisons, the conditions for studies in the historical control data must be generally similar. Significant factors affecting the background incidence of neoplasms at a variety of sites are diet, sex, strain/stock, and route of exposure. The NTP historical control database contains all 2-year studies for each species, sex, and strain/stock with histopathology findings in control animals completed within the most recent 5-year period^23-25^ for comparison across multiple technical reports. In general, the historical control data for a given study includes studies using the same route of administration, and the overall incidence of neoplasms in controls for all routes of administration are included for comparison.

## Quality Assurance Methods

The 2-year study was conducted in compliance with U.S. Food and Drug Administration Good Laboratory Practice Regulations.^26^ In addition, a draft of this NTP Technical Report was audited by an independent QA contractor against the study protocol and report. The audit findings were reviewed and assessed by Division of Translational Toxicology and National Center for Toxicological Research staff, and all comments were resolved or otherwise addressed during the preparation of this Technical Report.