# Introduction

## Chemical and Physical Properties

Triclosan (5-chloro-2-(2,4-dichlorophenoxy)phenol) (Figure 1) is a colorless to off-white crystalline powder with a slightly aromatic odor. It has a melting point of 55°C–57°C. Triclosan is slightly soluble in water (10 mg/L), moderately soluble in base (23.5 g/L in 0.1 N NaOH), and highly soluble (>1,000 g/L) in ethanol, acetone, propylene glycol, TWEEN^®^ 20, benzene, and methyl Cellosolve^®^.^1-3^

Figure 1

Triclosan (5-chloro-2-(2,4-dichlorophenoxy)phenol) (CASRN 3380-34-5; Chemical Formula: C_12_H_7_Cl_3_O_2_; Molecular Weight: 289.55)

Synonyms: 2,4,4-trichloro-2-hydroxydiphenyl ether, 2,4,4′-trichloro-2′-hydroxydiphenyl ether, trichloro-2′-hydroxydiphenyl ether.

Trade names: Irgasan, CH 3565, Irgasan CH 3565, Irgasan DP300, Ster-Zac, Tinosan AM110 Antimicrobial, Invasan DP 300R, Invasan DP 300 TEX, Irgaguard^®^ B 1000, VIV-20, Irgacare MP, Lexol 300, Cloxifenolum, Aquasept, Gamophen, Vinyzene DP 7000, Vinyzene SB-30, Sanitized Brand, Microbanish R, Vikol THP, Ultra-Fresh, Microban Additive “B,” AerisGuard, and Sapoderm.

## Production, Use, and Human Exposure

Triclosan is synthesized by reacting 2,4,4'-trichloro-2'-methoxydiphenyl ether with aluminum chloride (AlCl_3_). In the United States, the annual production of triclosan rose from 0.005–0.2 × 10^6^ kg in 1990 to >0.5–5 × 10^6^ kg in 1998, the last year for which data are available.^2^ Triclosan is formulated as an antimicrobial active component in consumer care products, such as soaps, deodorants, toothpastes, and mouthwashes; household cleaners; and textiles, such as sportswear, bed clothes, shoes, and carpets. Triclosan preparations are also used to control the spread of methicillin-resistant Staphylococcus aureus in clinical settings and surgical scrubs, preoperative skin preparations, and sutures to prevent bacterial colonization of surgical wounds. Triclosan has been found in drinking water, surface water, wastewater, and environmental sediments, as well as in human breast milk, plasma, and urine.^2-4^

## Biological and Toxicological Properties

### Absorption, Distribution, Metabolism, and Excretion

After oral exposure, triclosan is primarily absorbed through the mucosal membranes of the oral cavity and gastrointestinal tract. Dermal contact results in absorption through the skin.^2^ A dermal toxicokinetic study was conducted in male and female B6C3F1/N mice.^5^ When using 95% ethanol as the vehicle, mice fitted with Elizabethan collars (to prevent oral ingestion) absorbed approximately 85% of the total dose administered. In mice that did not have Elizabethan collars, an additional 16%–23% was absorbed. At a dose of 10 mg triclosan/kg body weight (mg/kg), the absorption of triclosan was 6% greater in female mice compared to male mice. Likewise, the area under the curve (AUC_0-∞_) and maximum observed concentration (C_max_) of triclosan in the plasma and liver were greater in females than in males.^5^ After absorption, triclosan is readily metabolized to glucuronide and sulfate conjugates as well as 2,4-dichlorophenol, hydroxytriclosan, and 4-chlorocatechol.^5,6^ Triclosan is excreted in the feces and urine. Rats and mice show predominantly biliary excretion into the feces, whereas guinea pigs excrete the majority of the dose via the kidney. In humans, urinary excretion is the major route of elimination.^2,3^

### Carcinogenicity

The carcinogenicity of triclosan has been investigated in male and female CD-1 mice administered 0, 10, 30, 100, or 200 mg/kg/day in the diet for 18 months. Doses ≥30 mg/kg/day resulted in a significant increase in hepatocellular neoplasms in both males and females. Doses ≤10 mg/kg/day did not induce a tumorigenic response. The incidences of hepatocellular adenoma and adenoma or carcinoma (combined) showed a clear dose-response, with the incidences being higher in males than in females.^3^ A dermal triclosan carcinogenic study was conducted in which 0.5% and 1% triclosan in acetone (approximately equivalent to 20 and 40 mg/kg/application, respectively) was applied to the shaved intrascapular region of Swiss mice three times per week for 18 months.^7^ Specific details of the study were not provided; however, the authors reported that the findings in the triclosan-exposed mice were similar to those in the control mice and that triclosan was not found to be carcinogenic.

## Study Rationale

There is potential for humans to be exposed to triclosan throughout their lifetime due to its extensive use in consumer care products and in clinical settings. Because there is very limited information regarding the dermal toxicity and carcinogenicity of triclosan, the U.S. Food and Drug Administration requested a dermal carcinogenicity study to conduct a safety assessment of triclosan-containing products.

Mice were used in this 2-year dermal carcinogenicity study because a previous oral carcinogenicity study in mice indicated that triclosan induced hepatocellular neoplasms.^3^ Furthermore, mice are the preferred species for dermal carcinogenicity studies under the U.S. Environmental Protection Agency’s Health Effects Test Guidelines “OPPTS 870.4300 Combined Chronic Toxicity/Carcinogenicity,”^8^ and, historically, NTP dermal carcinogenicity assessments have been conducted in mice.