# Acknowledgments

This study was conducted at the U.S. Food and Drug Administration’s (FDA’s) National Center for Toxicological Research under an Interagency Agreement between FDA and the National Institute of Environmental Health Sciences (NIEHS) (AES17011).This work was supported by the Intramural Research Program (ES103376, ES103377, ES103379, and ES103380) at NIEHS, National Institutes of Health and performed for the National Toxicology Program, Public Health Service, U.S. Department of Health and Human Services under contracts HHSN271201800012I, HHSN273201600020C, GS00Q14OADU417 (Order No. HHSN273201600015U), HHSN273201600011C, HHSN273201500014C, HHSN273201500006C, and HHSN316201200054W.