# Appendix E Supplemental Data

Tables with supplemental data can be found here: https://doi.org/10.22427/NTP-DATA-TR-604.^27^

## E.1 Two-year Study – Mice

### E.1.1 Data Tables

E01 – Animal Removal Summary by Treatment Group

E02 – Animals Removed from Experiment

Female Growth Curves

Female Survival and Body Weights

Male Growth Curves

Male Survival and Body Weights

P02 – Incidence Rates of Neoplasms by Anatomic Site

P03 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site

P04 – Neoplasms by Individual Animal

P05 – Incidence Rates of Neoplasms by Anatomic Site (Systemic Lesions Abridged)

P08 – Statistical Analysis of Primary Tumors – No Untreated

P08 – Statistical Analysis of Primary Tumors – Vehicle vs Untreated Control

P09 – Non-Neoplastic Lesions by Individual Animal

P10 – Statistical Analysis of Non-Neoplastic Lesions – Vehicle vs Untreated Control

P10 – Statistical Analysis of Non-Neoplastic Lesions – No Untreated

P11 – Statistical Analysis of Survival Data

P14 – Individual Animal Pathology Data

P17 – Neoplasms by Individual Animal (Systemic Lesions Abridged)

P18 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site with Average Severity Grades

P40 – Survival Curves

Triclosan In-life Observations at the Application Site

### E.1.2 Individual Animal Data

Female Individual Animal Neoplastic Pathology Data

Female Individual Animal Non-Neoplastic Pathology Data

Female Individual Animal Survival Data

Male Individual Animal Neoplastic Pathology Data

Male Individual Animal Non-Neoplastic Pathology Data

Male Individual Animal Survival Data