# Appendix D Benchmark Dose Analysis

## D.1 Methods

Benchmark doses (BMD) and the lower 95% confidence limits (BMDL) were calculated using U.S. Environmental Protection Agency Benchmark Dose Software (BMDS) version 2.4.0.70 (https://www.epa.gov/bmds). The calculations were conducted using gamma, logistic, log-logistic, log-probit, multistage, probit, and Weibull models to fit the incidences of neoplasms and nonneoplastic lesions and the doses of triclosan administered dermally. The BMD_10_ and BMDL_10_ were defined as the dose that caused a 10% excess risk of the specified adverse effect over that observed in the vehicle control group and as the 95% lower bound on the BMD corresponding to a 10% extra risk, respectively.

## D.2 Results

BMD modeling was conducted on neoplasms (hepatocellular carcinoma in male mice and pancreatic islet adenoma in female mice) and nonneoplastic lesions (hyperplasia, suppurative inflammation, and ulceration of the epidermis in male mice and hyperplasia of the epidermis, pancreatic ductal dilatation, and pituitary gland angiectasis and pars distalis hyperplasia in female mice) (Table D-1). The 95% lower bound on the BMD corresponding to a 10% extra risk (BMDL_10_) for hepatocellular carcinoma in male mice ranged from 1.1 to 2.4 mg triclosan/kg body weight/day (mg/kg/day), whereas the BMDL_10_ for pancreatic islet adenoma in female mice ranged from 11.7 to 12.3 mg/kg/day. In both male and female mice, the most sensitive nonneoplastic endpoint was epidermal hyperplasia. In male mice, the BMD calculations failed when using the entire epidermal hyperplasia data set. When the calculations were repeated without the 2.7 mg/kg/day group, the BMDL_10_ ranged from 1.6 to 2.8 mg/kg/day; when the 5.8 mg/kg/day group was eliminated, the comparable values were 0.88–0.93 mg/kg/day. In female mice, the BMDL_10_ for epidermal hyperplasia ranged from 1.5 to 3.0 mg/kg/day. Higher values were obtained for epidermal suppurative inflammation (3.1–7.6 mg/kg/day) and epidermal ulceration (6.6–9.7 mg/kg/day) in male mice and for pituitary gland angiectasis (5.1–8.3 mg/kg/day) and pars distalis hyperplasia (7.0–9.2 mg/kg/day) and pancreatic duct dilatation (11.2–11.6 mg/kg/day) in female mice.

Table D-1 Benchmark Dose Modeling Results for Select Neoplasms and Nonneoplastic Lesions in Male and Female Mice in the Two-year Dermal Study of Triclosan

Model | AIC | | | Fitted Model^a^ | GOF | | | BMD_10_ | BMDL_10_
Male
Epidermis, Hyperplasia
Gamma^b,c^ | 212.0 | | | 0.0009 | 0.0007 | | | 1.321 | 0.773
Logistic^b,c^ | 214.7 | | | 0.0003 | 0.0002 | | | 2.283 | 1.910
Log-logistic^b,c^ | 214.0 | | | 0.0003 | 0.0003 | | | 1.410 | 0.910
Log-probit^b,c^ | 213.3 | | | 0.0004 | 0.0004 | | | 1.464 | 0.991
Multistage^b,c^ | 211.1 | | | 0.0013 | 0.0011 | | | 1.198 | 0.807
Probit^b,c^ | 213.7 | | | 0.0005 | 0.0003 | | | 2.149 | 1.819
Weibull^b,c^ | 211.7 | | | 0.0010 | 0.0008 | | | 1.314 | 0.796
Epidermis, Hyperplasia (minus the 2.7 mg/kg/day group)
Gamma | 133.1 | | | 0.489 | 0.485 | | | 2.987 | 1.808
Logistic | 131.2 | | | 0.755 | 0.774 | | | 3.171 | 2.551
Log-logistic | 133.6 | | | 0.316 | 0.324 | | | 3.851 | 2.572
Log-probit | 133.7 | | | 0.297 | 0.308 | | | 3.968 | 2.771
Multistage | 133.2 | | | 0.467 | 0.467 | | | 2.672 | 1.551
Probit | 130.9 | | | 0.897 | 0.903 | | | 2.928 | 2.365
Weibull | 133.1 | | | 0.489 | 0.485 | | | 2.987 | 1.808
Epidermis, Hyperplasia (minus the 5.8 mg/kg/day group)
Gamma^c^ | 140.5 | | | 0.025 | 0.030 | | | 1.100 | 0.642
Logistic^b,c^ | 150.1 | | | 0.0002 | 0.0003 | | | 2.015 | 1.602
Log-logistic | 138.2 | | | 0.098 | 0.109 | | | 1.262 | 0.884
Log-probit | 137.9 | | | 0.116 | 0.125 | | | 1.303 | 0.932
Multistage^c^ | 142.0 | | | 0.011 | 0.016 | | | 0.849 | 0.561
Probit^b,c^ | 149.4 | | | 0.0004 | 0.0004 | | | 1.962 | 1.608
Weibull^c^ | 141.0 | | | 0.018 | 0.024 | | | 1.001 | 0.602
Epidermis, Inflammation, Suppurative
Gamma | 110.0 | | | 0.931 | 0.900 | | | 6.160 | 4.236
Logistic | 113.9 | | | 0.429 | 0.639 | | | 9.383 | 7.568
Log-logistic | 109.9 | | | 0.941 | 0.920 | | | 6.020 | 4.005
Log-probit | 111.9 | | | 0.857 | 0.853 | | | 5.708 | 3.105
Multistage | 110.0 | | | 0.931 | 0.900 | | | 6.160 | 4.236
Probit | 113.7 | | | 0.469 | 0.665 | | | 8.994 | 7.101
Weibull | 110.0 | | | 0.931 | 0.900 | | | 6.160 | 4.236
Epidermis, Ulcer
Gamma | | 81.2 | 0.540 | | | 0.508 | 12.884 | | | 6.865
Logistic | | 81.6 | 0.472 | | | 0.578 | 13.086 | | | 9.711
Log-logistic | | 81.2 | 0.544 | | | 0.503 | 12.845 | | | 6.697
Log-probit | | 80.5 | 0.696 | | | 0.699 | 17.731 | | | 6.553
Multistage | | 81.2 | 0.540 | | | 0.507 | 12.884 | | | 6.865
Probit | | 81.5 | 0.479 | | | 0.572 | 13.128 | | | 9.360
Weibull | | 81.2 | 0.540 | | | 0.507 | 12.884 | | | 6.865
Hepatocellular Carcinoma
Gamma | | 324.3 | 0.836 | | | 0.836 | 2.636 | | | 1.591
Logistic | | 324.8 | 0.729 | | | 0.729 | 3.429 | | | 2.353
Log-logistic | | 324.0 | 0.912 | | | 0.912 | 2.081 | | | 1.101
Log-probit^d^ | | 325.8 | 0.866 | | | 0.866 | 1.417 | | | 0.017
Multistage | | 324.3 | 0.836 | | | 0.836 | 2.636 | | | 1.591
Probit | | 324.8 | 0.733 | | | 0.732 | 3.401 | | | 2.335
Weibull | | 324.3 | 0.836 | | | 0.836 | 2.636 | | | 1.591
Female
Epidermis, Hyperplasia
Gamma^c^ | | 183.6 | 0.006 | | | 0.030 | 4.824 | | | 1.366
Logistic | | 178.2 | 0.078 | | | 0.166 | 3.594 | | | 2.998
Log-logistic^c^ | | 183.5 | 0.007 | | | 0.032 | 4.954 | | | 2.647
Log-probit^b,c^ | | 186.7 | 0.002 | | | 0.002 | 1.928 | | | 1.361
Multistage | | 178.4 | 0.074 | | | 0.071 | 2.114 | | | 1.461
Probit | | 178.2 | 0.080 | | | 0.148 | 3.285 | | | 2.758
Weibull^c^ | | 182.4 | 0.011 | | | 0.034 | 3.823 | | | 1.468
Pancreas, Duct Dilatation
Gamma | | 39.0 | 0.425 | | | 0.389 | 13.520 | | | 11.446
Logistic | | 39.2 | 0.393 | | | 0.381 | 14.781 | | | 11.628
Log-logistic | | 39.2 | 0.382 | | | 0.487 | 20.488 | | | 11.195
Log-probit | | 39.3 | 0.370 | | | 0.496 | 24.011 | | | 11.232
Multistage | | 39.1 | 0.395 | | | 0.488 | 18.402 | | | 11.254
Probit | | 39.2 | 0.387 | | | 0.387 | 15.396 | | | 11.480
Weibull | | 39.0 | 0.425 | | | 0.389 | 12.905 | | | 11.424
Pancreas, Islets, Adenoma
Gamma | | 39.0 | 0.425 | | | 0.389 | 13.520 | | | 11.752
Logistic | | 40.4 | 0.235 | | | 0.178 | 15.720 | | | 11.813
Log-logistic | | 39.0 | 0.425 | | | 0.389 | 12.922 | | | 11.833
Log-probit | | 41.0 | 0.248 | | | 0.221 | 13.190 | | | 11.675
Multistage | | 40.3 | 0.248 | | | 0.309 | 19.173 | | | 12.272
Probit | | 40.6 | 0.215 | | | 0.177 | 16.973 | | | 11.847
Weibull | | 39.0 | 0.425 | | | 0.389 | 12.905 | | | 11.859
Pituitary Gland, Angiectasis
Gamma | | 111.3 | 0.580 | | | 0.593 | 12.137 | | | 5.991
Logistic | | 109.2 | 0.798 | | | 0.800 | 11.297 | | | 8.313
Log-logistic | | 111.3 | 0.580 | | | 0.592 | 12.154 | | | 5.811
Log-probit | | 111.3 | 0.580 | | | 0.593 | 12.106 | | | 5.100
Multistage | | 111.3 | 0.578 | | | 0.587 | 11.232 | | | 5.988
Probit | | 109.3 | 0.791 | | | 0.795 | 11.211 | | | 7.945
Weibull | | 111.3 | 0.580 | | | 0.592 | 12.162 | | | 5.991
Pituitary Gland, Pars Distalis, Hyperplasia
Gamma | | 143.9 | 0.357 | | | 0.421 | 11.924 | | | 9.142
Logistic | | 146.0 | 0.147 | | | 0.247 | 11.466 | | | 7.567
Log-logistic | | 143.9 | 0.358 | | | 0.422 | 12.263 | | | 9.139
Log-probit | | 145.9 | 0.199 | | | 0.245 | 12.106 | | | 9.068
Multistage | | 145.5 | 0.185 | | | 0.280 | 11.841 | | | 7.046
Probit | | 146.1 | 0.141 | | | 0.240 | 11.623 | | | 7.318
Weibull | | 143.9 | 0.358 | | | 0.422 | 12.277 | | | 9.169

AIC = Akaike information criterion; GOF = goodness of fit p value; BMD_10_ = benchmark dose corresponding to a 10% extra risk of the specified adverse effect over that observed in the vehicle control group; BMDL_10_ = 95% lower bound on the benchmark dose corresponding to a 10% extra risk of the specified adverse effect over that observed in the vehicle control group

^a^ P value of fitted model compared to the full model.

^b^ Model rejected because scaled residual for one or more of the doses in GOF determination was >|2.00|.

^c^ Model rejected because fitted model and/or GOF p value ≤0.05.

^d^ Due to the disparity between the BMDL_10_ obtained from the log-probit model and the BMDL_10_ obtained from the other models, the log-probit BMDL_10_ value was not considered further.