# Appendix C Sentinel Animal Program

## C.1 Methods

Rodents used in the National Toxicology Program are produced in optimally clean facilities to eliminate potential pathogens that might affect study results. The Sentinel Animal Program is part of the periodic monitoring of animal health that occurs during the toxicological evaluation of test compounds. Under this program, the disease state of the rodents is monitored via sera or feces from extra (sentinel) or exposed animals in the study rooms. The sentinel animals and the study animals are subject to identical environmental conditions. Furthermore, the sentinel animals come from the same production source and weanling groups as the animals used for the studies of test compounds.

For this toxicology and carcinogenesis study, blood samples were collected from each sentinel animal and allowed to clot, and the serum was separated. All samples were processed appropriately with serology by IDEXX BioResearch (formerly Rodent Animal Diagnostic Laboratory [RADIL], University of Missouri, Columbia, MO) for determination of the presence of pathogens. Evaluation for endo- and ectoparasites was performed at the U.S. Food and Drug Administration’s National Center for Toxicological Research.

The laboratory methods and agents for which testing was performed in the sentinel animals are tabulated in Table C-1 below; the times at which samples were collected during the study are also listed.

## C.2 Results

All test results were negative.

Table C-1 Methods and Results for Sentinel Animal Testing in Male and Female Mice

Collection Time Points | Quarantine | 3 Months | 6 Months | 9 Months | 12 Months | 15 Months | 18 Months | 21 Months | Study Termination
Number Examined (Males/Females) | 12/12 | 2/2 | 2/2 | 2/2 | 2/2 | 2/2 | 2/2 | 2/2 | 2/2
Method/Test
Multiplex Fluorescent Immunoassay (MFI)
Ectromelia | − | − | − | − | − | − | − | − | −
Epizootic diarrhea of infant mice (EDIM) | − | − | − | − | − | − | − | − | −
Lymphocytic choriomeningitis virus (LCM) | − | − | − | − | − | − | − | − | −
Mycoplasma pulmonis | − | − | − | − | − | − | − | − | −
Mouse hepatitis virus (MHV) | − | − | − | − | − | − | − | − | −
Parvo NS-1 | − | − | − | − | − | − | − | − | −
Polyoma | − | − | − | − | − | − | − | − | −
Mouse parvovirus (MPV) | − | − | − | − | − | − | − | − | −
Minute virus of mice (MMV) | − | − | − | − | − | − | − | − | −
Pneumonia virus of mice (PVM) | − | − | − | − | − | − | − | − | −
Reovirus Type 3 (REO3) | − | − | − | − | − | − | − | − | −
Sendai | − | − | − | − | − | − | − | − | −
Theiler’s murine encephalomyelitis virus (TMEV) | − | − | − | − | − | − | − | − | −
In-house Evaluation
Endoparasite evaluation | − | − | − | − | − | − | − | − | −
Ectoparasite evaluation | − | − | − | − | − | − | − | − | −
Polymerase Chain Reaction (PCR)
Helicobacter hepaticus | − | − | − | − | − | − | − | − | −
Routine Culturing
Bordetella bronchiseptica | − | − | − | − | − | − | − | − | −
Citrobacter freundii | − | − | − | − | − | − | − | − | −
Corynebacterium kutscheri | − | − | − | − | − | − | − | − | −
Erysipelothrix rhusiopathiae | − | − | − | − | − | − | − | − | −
Klebsiella oxytoca | − | − | − | − | − | − | − | − | −
Klebsiella pneumonia | − | − | − | − | − | − | − | − | −
Listeria monocytogenes | − | − | − | − | − | − | − | − | −
Pasteurella pneumotropica | − | − | − | − | − | − | − | − | −
Pasteurella multocida | − | − | − | − | − | − | − | − | −
Pseudomonas aeruginosa | − | − | − | − | − | − | − | − | −
Salmonella sp. | − | − | − | − | − | − | − | − | −
Streptococcus pneumoniae | − | − | − | − | − | − | − | − | −

− = negative.