# Appendix B Ingredients, Nutrient Composition, and Contaminant Levels in NTP-2000 Mouse Ration

## B.1 NTP-2000 Feed

Table B-1 Ingredients of NTP-2000 Mouse Ration

Ingredients | Percent by Weight
Ground Hard Winter Wheat | 23.00
Ground #2 Yellow Shelled Corn | 22.44
Wheat Middlings | 15.00
Oat Hulls | 8.50
Alfalfa Meal (Dehydrated, 17% Protein) | 7.50
Purified Cellulose | 5.50
Soy Protein Concentrate | 4.00
Fish Meal (60% Protein) | 4.00
Corn Oil (Without Preservatives) | 3.00
Soy Oil (Without Preservatives) | 3.00
Dried Brewer’s Yeast | 1.00
Calcium Carbonate (USP) | 0.90
Vitamin Premix^a^ | 0.50
Mineral Premix^b^ | 0.50
Calcium Phosphate, Dibasic (USP) | 0.40
Sodium Chloride | 0.30
Choline Chloride (70% Choline) | 0.26
Methionine | 0.20

USP = United States Pharmacopeia.

^a^ Wheat middlings as carrier.

^b^ Calcium carbonate as carrier.

Table B-2 Vitamins and Minerals in NTP-2000 Mouse Ration

| Amount^a^ | Source
Vitamins
Vitamin A | 4,000 IU | Stabilized vitamin A palmitate or acetate
Vitamin D | 1,000 IU | D-activated animal sterol
Vitamin K | 1.0 mg | Menadione sodium bisulfite complex
α-Tocopheryl Acetate | 100 IU | –
Niacin | 23 mg | –
Folic Acid | 1.1 mg | –
d-Pantothenic Acid | 10 mg | d-Calcium pantothenate
Riboflavin | 3.3 mg | –
Thiamine | 4 mg | Thiamine mononitrate
B12 | 52 µg | –
Pyridoxine | 6.3 mg | Pyridoxine hydrochloride
Biotin | 0.2 mg | d-Biotin
Minerals
Magnesium | 514 mg | Magnesium oxide
Iron | 35 mg | Iron sulfate
Zinc | 12 mg | Zinc oxide
Manganese | 10 mg | Manganese oxide
Copper | 2.0 mg | Copper sulfate
Iodine | 0.2 mg | Calcium iodate
Chromium | 0.2 mg | Chromium acetate

^a^ Per kg of finished diet.

Table B-3 Nutrient Composition of NTP-2000 Mouse Ration

Nutrient | Mean ± Standard Deviation | Range | Number of Samples
Protein (% by Weight) | 14.72 ± 0.4622 | 14.1–15.5 | 13
Crude Fat (% by Weight) | 7.96 ± 0.9014 | 5.1–8.7 | 13
Crude Fiber (% by Weight) | 9.22 ± 0.6446 | 7.7–10.1 | 13
Ash (% by Weight) | 5.33 ± 1.320 | 4.72–9.7 | 13
Amino Acids (% of Total Diet)
Arginine | 0.806 ± 0.074 | 0.67–0.97 | 30
Cystine | 0.220 ± 0.0212 | 0.15–0.25 | 30
Glycine | 0.702 ± 0.037 | 0.62–0.8 | 30
Histidine | 0.341 ± 0.0692 | 0.27–0.68 | 30
Isoleucine | 0.548 ± 0.0393 | 0.43–0.66 | 30
Leucine | 1.096 ± 0.062 | 0.96–1.24 | 30
Lysine | 0.699 ± 0.1027 | 0.31–0.86 | 30
Methionine | 0.409 ± 0.041 | 0.26–0.49 | 30
Phenylalanine | 0.623 ± 0.046 | 0.471–0.72 | 30
Threonine | 0.513 ± 0.041 | 0.43–0.61 | 30
Tryptophan | 0.156 ± 0.0262 | 0.11–0.2 | 30
Tyrosine | 0.423 ± 0.649 | 0.28–0.54 | 30
Valine | 0.666 ± 0.039 | 0.55–0.73 | 30
Essential Fatty Acids (% of Total Diet)
Linoleic | 3.94 ± 0.233 | 3.49–4.55 | 30
Linolenic | 0.31 ± 0.030 | 0.21–0.368 | 30
Vitamins
Vitamin A (IU/kg) | 4,225 ± 83.87 | 3,040–6,210 | 13
Vitamin D (IU/kg) | 1,000^a^ | – | –
α-Tocopherol (ppm) | 2,376 ± 12,602 | 13.6–69,100 | 30
Thiamine (ppm)^b^ | 13.6 ± 20.31 | 6.6–81.0 | 13
Riboflavin (ppm) | 8.17 ± 2.792 | 4.2–17.5 | 30
Niacin (ppm) | 79.19 ± 8.50 | 66.4–98.2 | 30
Pantothenic Acid (ppm) | 26.33 ± 10.87 | 17.4–81 | 30
Pyridoxine (ppm)^b^ | 9.72 ± 2.018 | 6.44–14.3 | 30
Folic Acid (ppm) | 1.6 ± 0.44 | 1.15–3.27 | 30
Biotin (ppm) | 0.33 ± 0.10 | 0.2–0.704 | 30
Vitamin B_12_ (ppb) | 50.06 ± 34.34 | 18.3–174 | 30
Choline (as Chloride) (ppm) | 2,572 ± 634 | 1,160–3,790 | 30
Minerals
Calcium (%) | 0.950 ± 0.0532 | 0.863–1.02 | 13
Phosphorus (%) | 0.582 ± 0.032 | 0.525–0.639 | 13
Potassium (%) | 0.680 ± 0.029 | 0.626–0.733 | 30
Chloride (%) | 0.391 ± 0.044 | 0.3–0.517 | 30
Sodium (%) | 0.194 ± 0.0274 | 0.153–0.283 | 30
Magnesium (%) | 0.217 ± 0.053 | 0.185–0.49 | 30
Iron (ppm) | 190.43 ± 36.106 | 135–311 | 30
Manganese (ppm) | 50.02 ± 9.27 | 21.0–73.1 | 30
Zinc (ppm) | 56.81 ± 25.25 | 42.5–184.0 | 30
Copper (ppm) | 7.61 ± 2.46 | 3.21–16.3 | 30
Iodine (ppm) | 0.514 ± 0.217 | 0.0–0.972 | 30
Chromium (ppm) | 1.119 ± 1.16 | 0.33–3.97 | 30
Cobalt (ppm) | 0.219 ± 0.150 | 0.0857–0.864 | 28

^a^ From formulation.

^b^ As hydrochloride.

Table B-4 Contaminant Levels in NTP-2000 Mouse Ration

| Mean ± Standard Deviation | Range | Number of Samples
Contaminants
Arsenic (ppm) | 0.2228 ± 0.018 | 0.196–0.262 | 13
Cadmium (ppm) | 0.0507 ± 0.004 | 0.045–0.058 | 13
Lead (ppm) | 0.1434 ± 0.1458 | 0.06–0.621 | 13
Mercury (ppm) | 0.0104 ± 0.0014 | 0.01–0.015 | 13
Selenium (ppm) | 0.1871 ± 0.0318 | 0.135–0.251 | 13
Aflatoxins (ppb)^a^ | 5 | – | 13
Nitrate Nitrogen (ppm)^b^ | 15.692 ± 5.813 | 9.91–27.4 | 13
Nitrite Nitrogen (ppm)^b^ | 0.395 ± 0.245 | 0.12–0.63 | 13
BHA (ppm)^c^ | 1.412 ± 1.064 | 1.0–4.76 | 13
BHT (ppm)^a,c^ | 1 | – | 13
Aerobic Plate Count (CFU/g) | 10.08 ± 3.883 | 1.0–20.0 | 13
Coliform (MPN/g)^a^ | 3 | – | 13
Escherichia coli (MPN/g) | 4.615 ± 3.070 | 3.0–10.0 | 13
Salmonella (MPN/g) | Negative | – | 13
Total Nitrosamines (ppb)^d^ | 9.964 ± 4.071 | 0.0–14.1 | 11
N-Nitrosodimethylamine (ppb)^d^ | 2.51 ± 2.365 | 0.0–7.9 | 11
N-Nitrosopyrrolidine (ppb)^d^ | 7.455 ± 3.02 | 0.0–11.9 | 11
Pesticides (ppm)
α-BHC^a^ | <0.01 | – | 13
β-BHC^a^ | <0.02 | – | 13
γ-BHC^a^ | <0.01 | – | 13
δ-BHC^a^ | <0.01 | – | 13
Heptachlor^a^ | <0.01 | – | 13
Aldrin^a^ | <0.01 | – | 13
Heptachlor Epoxide^a^ | <0.01 | – | 13
DDE^a^ | <0.01 | – | 13
DDD^a^ | <0.01 | – | 13
DDT^a^ | <0.01 | – | 13
HCB^a^ | <0.01 | – | 13
Mirex^a^ | <0.01 | – | 13
Methoxychlor^a^ | <0.05 | – | 13
Dieldrin^a^ | <0.01 | – | 13
Endrin^a^ | <0.01 | – | 13
Telodrin^a^ | <0.01 | – | 13
Chlordane^a^ | <0.05 | – | 13
Toxaphene^a^ | <0.10 | – | 13
Estimated PCBs^a^ | <0.20 | – | 13
Ronnel^a^ | <0.01 | – | 13
Ethion^a^ | <0.02 | – | 13
Trithion^a^ | <0.05 | – | 13
Diazinon^a^ | <0.10 | – | 13
Methyl Chlorpyrifos | 0.139 ± 0.1076 | 0.02–0.686 | 13
Methyl Parathion^a^ | <0.02 | – | 13
Ethyl Parathion^a^ | <0.02 | – | 13
Malathion | 0.107 ± 0.155 | 0.02–0.585 | 13
Endosulfan I^a^ | <0.01 | – | 13
Endosulfan II^a^ | <0.01 | – | 13
Endosulfan Sulfate^a^ | <0.03 | – | 13

All samples were irradiated.

BHA = butylated hydroxyanisole; BHT = butylated hydroxytoluene; CFU = colony-forming units; MPN = most probable number; BHC = hexachlorocyclohexane or benzene hexachloride; DDE = dichlorodiphenyldichloroethylene; DDD = dichlorodiphenyldichloroethane; DDT = dichlorodiphenyltrichloroethane; HCB = hexachlorobenzene; PCB = polychlorinated biphenyl.

^a^ All values were below the detection limit. The detection limit is given as the mean.

^b^ Sources of contamination include alfalfa, grains, and fish meal.

^c^ Sources of contamination include soy oil and fish meal.

^d^ All values were corrected for percent recovery.