# Appendix A Chemical Characterization and Dose Formulation Studies

## A.1 Procurement and Characterization

### A.1.1 Triclosan

Triclosan was obtained from Alfa Aesar (Ward Hill, MA) in a single lot (5001A29X). Identity, purity, and stability analyses were conducted by the study laboratory at the U.S. Food and Drug Administration’s National Center for Toxicological Research (NCTR, Jefferson, AR). Reports on analyses performed in support of the triclosan studies are on file at the National Institute of Environmental Health Sciences.

The identity of the test lot was evaluated using ^1^H nuclear magnetic resonance (NMR) spectroscopy. The ^1^H NMR spectrum was consistent with the structure of triclosan and identical to that of the reference standard (lot 1412854V, Sigma Aldrich, St. Louis, MO) (Figure A-1). No resonances due to contaminants were present in the spectrum except those produced by water and solvent. The identity of lot 5001A29X was further confirmed using mass spectrometry (MS) after separation by high-performance liquid chromatography (HPLC) with diode array detection (PDA) (Table A-1, System A). The MS spectrum was consistent with the structure of triclosan, which confirmed that the test lot corresponded to triclosan.

Purity evaluation was conducted by HPLC/PDA (Table A-1, System B) using a 1.0 mg/mL sample of the test lot dissolved in methanol. No impurities were identified using HPLC/PDA. The overall purity of lot 5001A29X was estimated to be 99.9% by comparing the peak area with the reference standard, which was consistent with the 99.0% purity indicated by the manufacturer. The ^1^H NMR analysis of the test article was consistent with this purity determination. Additionally, the test lot matched the reference standard’s HPLC retention time and ultraviolet (UV) spectrum. Repeated purity evaluation conducted at the end of the study confirmed a purity of 99.9%.

The test article was received in amber jars and stored at room temperature.

### A.1.2 Ethanol

The 95% ethanol dose vehicle was obtained from Decon Laboratories (King of Prussia, PA) in a single lot (2801G). The identity of ethanol was confirmed using ^1^H NMR spectroscopy. The NMR spectrum was consistent with the structure of ethanol, and there was no evidence of contamination by other proton-containing compounds (Figure A-2).

Purity evaluation of lot 2801G was conducted by the study laboratory using HPLC/PDA (Table A-1, System B). The chromatograms did not show any UV chromophore-containing components above background, confirming a purity consistent with the 95% purity specified by the vendor. Batches of the ethanol dose vehicle were evaluated for the presence of triclosan before and after the study, and no triclosan was detected.

The ethanol dose vehicle was received in amber glass containers and stored at room temperature.

## A.2 Preparation and Analysis of Dose Formulations

Dose formulations of triclosan (lot 5001A29X) in 95% ethanol were prepared by Priority One Services (Alexandria, VA) following the protocols outlined in Table A-2. Dose formulations were prepared at 1.25, 2.7, 5.8, and 12.5 mg/L (25 preparations; September 2013–August 2015) and were refrigerated, protected from light, and used within approximately 1 month of mixing.

Stability studies of the dose formulations stored at room (25°C) or refrigerated (2°C–8°C) temperatures were conducted using HPLC/PDA (Table A-1, System B). The lowest (1.25 mg/mL) and highest (12.5 mg/mL) dose formulations were evaluated after 8 weeks at refrigerated temperatures or 4 weeks at room temperature. Stability for up to 56 days under refrigerated temperatures was confirmed. The dose formulations were also found to be homogeneous, as the percent coefficient of variation (%CV) values of three replicate samples per dose preparation were all ≤10%, with one exception: the 2.7 mg/mL formulation prepared on January 13, 2014, had a %CV value of 10.6%.

Analyses of preadministration dose formulations were conducted by the study laboratory using HPLC/PDA (Table A-1, System B). All dose formulations were within 10% of the target concentrations, with one exception: the 12.5 mg/mL formulation prepared on February 19, 2014, had a concentration of only 1.31 mg/mL. However, this dose was remixed on February 21, 2014, and the new solution was within 10% of the target concentration (Table A-3).

## A.3 Analysis of Triclosan in Experimental Background Materials

The animal feed (NTP-2000 Irradiated Rodent Diet) and drinking water (Millipore-filtered drinking water) were analyzed for the presence of background triclosan using ultra-performance liquid chromatography (UPLC) with MS (Table A-1, System C). Animal feed samples were ground to a powder and extracted with acetonitrile. The acetonitrile supernatant was assayed by UPLC-MS and compared with feed samples spiked at 1 ppm triclosan. Although a prominent triclosan peak was observed in the spiked samples, the peak was not detectable in the unspiked samples, indicating that any possible background levels of triclosan in the feed were not present at or above 1 ppm. Additionally, peak areas observed for triclosan in the three drinking water samples were negligible in comparison with water samples spiked at 1 ppm triclosan, indicating that the drinking water triclosan levels were not present at or above 1 ppm.

Table A-1 Liquid Chromatography Systems Used in the Two-year Dermal Study of Triclosan

Chromatography | Detection System | Column | Mobile Phase
System A
High-performance liquid chromatography | Diode array detector (200–400 nm) and tandem mass spectrometry (ESI) | Waters Acquity BEH C18 (2.1 × 50 mm, 1.7 μm particle size) | A: Acetonitrile B: Water Gradient program: A:B 20:80 to 90:10 in 4 min 500 μL/min flow rate
System B
High-performance liquid chromatography | Diode array detector (190–400 nm) | Waters Novapak-C18 (3.9 mm × 150 mm, 4 μm particle size) | A: 5 mM phosphate buffer:methanol, pH 2.5 (95:5) B: 5 mM phosphate buffer:methanol, pH 2.5 (5:95) Gradient program: A:B 100:0 hold for 3 min; 0:100 for 9.5 min at gradient curve 6; 0:100 for 0.75 min at gradient curve 11; 100:0 for 26.75 min at gradient curve 11.
System C
Ultra-performance liquid chromatography | Mass spectrometry (ESI) | Waters Acquity BEH C18 (1.2 mm × 50 mm, 1.7 μm particle size) | A: Water B: Acetonitrile Gradient program: A:B 80:20 hold for 4 min; 10:90 for 0.1 min at gradient curve 6; 80:20 for 1.9 min at gradient curve 6.

ESI = electrospray ionization.

Table A-2 Preparation and Storage of Dose Formulations Administered to Mice in the Two-year Dermal Study of Triclosan

Preparation
Formulations were prepared by weighing the required amount of triclosan powder into a glass beaker and pouring ~70% of the required ethanol volume into the beaker. Formulations were stirred with a stir bar for ~5 minutes and transferred to a volumetric flask. The remaining ethanol was added with a syringe or pipette, and the flask was inverted several times to mix. The formulations were transferred into the required number of amber glass, screw-top bottles for dosing. Additional mixing occurred as needed during storage.
Chemical Lot Number
5001A29X (Alfa Aesar, Ward Hill, MA)
Vehicle Lot Number
2801G (Decon Laboratories, King of Prussia, PA)
Maximum Storage Time
56 days
Storage Conditions
Amber glass bottles at 2°C–8°C
Study Laboratory
National Center for Toxicological Research (Jefferson, AR)

Table A-3 Results of Analyses of Dose Formulations Administered to Mice in the Two-year Dermal Study of Triclosan

Date Prepared | Date Analyzed | Target Concentration (mg/mL) | Determined Concentration (mg/mL)^a^ | Difference from Target (%)
September 5, 2013 | September 10, 2013 | 0 | BLOQ | NA
| | 1.25 | 1.29 ± 0.09 | 3.2
| | 2.7 | 2.93 ± 0.22 | 8.5
| | 5.8 | 6.03 ± 0.17 | 4.0
| | 12.5 | 12.1 ± 0.18 | −3.2
September 23, 2013 | September 25, 2013 | 0 | BLOQ | NA
| | 1.25 | 1.20 ± 0.05 | −4.0
| | 2.7 | 2.68 ± 0.2 | −0.7
| | 5.8 | 5.86 ± 0.2 | 1.0
| | 12.5 | 13.1 ± 1.0 | 4.8
September 30, 2013 | October 9, 2013 | 0 | BLOQ | NA
| | 1.25 | 1.24 ± 0.10 | −0.8
| | 2.7 | 2.80 ± 0.01 | 3.7
| | 5.8 | 5.70 ± 0.46 | −1.7
| | 12.5 | 13.6 ± 0.4 | 8.8
November 4, 2013 | November 6, 2013 | 0 | BLOQ | NA
| | 1.25 | 1.32 ± 0.01 | 5.6
| | 2.7 | 2.85 ± 0.01 | 5.6
| | 5.8 | 5.83 ± 0.07 | 0.5
| | 12.5 | 11.9 ± 1.2 | −4.8
December 10, 2013 | December 16, 2013 | 0 | BLOQ | NA
| | 1.25 | 1.16 ± 0.09 | −7.2
| | 2.7 | 2.51 ± 0.25 | −7.0
| | 5.8 | 5.68 ± 0.4 | −2.1
| | 12.5 | 12.6 ± 0.16 | 0.8
January 13, 2014 | January 15, 2014 | 0 | BLOQ | NA
| | 1.25 | 1.25 ± 0.11 | 0.0
| | 2.7 | 2.96 ± 0.31 | 9.6
| | 5.8 | 6.04 ± 0.48 | 4.1
| | 12.5 | 13.0 ± 1.25 | 4.0
February 19, 2014 | February 21, 2014 | 0 | BLOQ | NA
| | 1.25 | 1.37 ± 0.06 | 9.6
| | 2.7 | 2.72 ± 0.21 | 0.7
| | 5.8 | 5.99 ± 0.22 | 3.3
| | 12.5^b^ | 12.0 ± 0.35 | −4.0
March 18, 2014 | March 20, 2014 | 0 | BLOQ | NA
| | 1.25 | 1.37 ± 0.05 | 9.6
| | 2.7 | 2.74 ± 0.19 | 1.5
| | 5.8 | 5.75 ± 0.31 | −0.9
| | 12.5 | 13.1 ± 0.54 | 4.8
April 21, 2014 | April 22, 2014 | 0 | BLOQ | NA
| | 1.25 | 1.25 ± 0.09 | 0.0
| | 2.7 | 2.72 ± 0.01 | 0.7
| | 5.8 | 5.69 ± 0.11 | −1.9
| | 12.5 | 12.9 ± 0.2 | 3.2
May 21, 2014 | May 23, 2014 | 0 | BLOQ | NA
| | 1.25 | 1.29 ± 0.01 | 3.2
| | 2.7 | 2.75 ± 0.02 | 1.9
| | 5.8 | 5.95 ± 0.05 | 2.6
| | 12.5 | 12.8 ± 0.10 | 2.4
June 18, 2014 | June 19, 2014 | 0 | BLOQ | NA
| | 1.25 | 1.26 ± 0.05 | 0.8
| | 2.7 | 2.77 ± 0.01 | 2.6
| | 5.8 | 5.9 ± 0.02 | 1.7
| | 12.5 | 12.6 ± 0.07 | 0.8
July 15, 2014 | July 16, 2014 | 0 | BLOQ | NA
| | 1.25 | 1.25 ± 0.01 | 0.0
| | 2.7 | 2.69 ± 0.03 | −0.4
| | 5.8 | 5.76 ± 0.04 | −0.7
| | 12.5 | 12.3 ± 0.33 | −1.6
August 19, 2014 | August 21, 2014 | 0 | BLOQ | NA
| | 1.25 | 1.23 ± 0.02 | −1.6
| | 2.7 | 2.61 ± 0.03 | −3.3
| | 5.8 | 5.49 ± 0.07 | −5.3
| | 12.5 | 12.0 ± 0.57 | −4.0
September 22, 2014 | September 25, 2014 | 0 | BLOQ | NA
| | 1.25 | 1.31 ± 0.06 | 4.8
| | 2.7 | 2.78 ± 0.1 | 3.0
| | 5.8 | 5.91 ± 0.57 | 1.9
| | 12.5 | 13.4 ± 0.13 | 7.2
October 21, 2014 | October 24, 2014 | 0 | BLOQ | NA
| | 1.25 | 1.36 ± 0.00 | 8.8
| | 2.7 | 2.75 ± 0.19 | 1.9
| | 5.8 | 6.18 ± 0.01 | 6.6
| | 12.5 | 13.3 ± 0.36 | 6.4
November 17, 2014 | November 20, 2014 | 0 | BLOQ | NA
| | 1.25 | 1.26 ± 0.02 | 0.8
| | 2.7 | 2.65 ± 0.02 | −1.9
| | 5.8 | 5.45 ± 0.12 | −6.0
| | 12.5 | 12.0 ± 0.12 | −4.0
December 15, 2014 | December 19, 2014 | 0 | BLOQ | NA
| | 1.25 | 1.24 ± 0.04 | −0.8
| | 2.7 | 2.56 ± 0.07 | −5.2
| | 5.8 | 5.64 ± 0.21 | −2.8
| | 12.5 | 11.6 ± 0.34 | −7.2
January 13, 2015 | January 16, 2015 | 0 | BLOQ | NA
| | 1.25 | 1.22 ± 0.04 | −2.4
| | 2.7 | 2.64 ± 0.04 | −2.2
| | 5.8 | 6.18 ± 0.05 | 6.6
| | 12.5 | 12.6 ± 0.9 | 0.8
February 18, 2015 | February 27, 2015 | 0 | BLOQ | NA
| | 1.25 | 1.24 ± 0.09 | −0.8
| | 2.7 | 2.64 ± 0.12 | −2.2
| | 5.8 | 5.71 ± 0.17 | −1.6
| | 12.5 | 12.4 ± 0.4 | −0.8
March 16, 2015 | March 20, 2015 | 0 | BLOQ | NA
| | 1.25 | 1.33 ± 0.04 | 6.4
| | 2.7 | 2.63 ± 0.2 | −2.6
| | 5.8 | 6.07 ± 0.38 | 4.7
| | 12.5 | 12.8 ± 0.6 | 2.4
April 14, 2015 | April 16, 2015 | 0 | BLOQ | NA
| | 1.25 | 1.33 ± 0.1 | 6.4
| | 2.7 | 2.79 ± 0.1 | 3.3
| | 5.8 | 5.86 ± 0.27 | 1.0
| | 12.5 | 13.2 ± 0.1 | 5.6
May 18, 2015 | May 20, 2015 | 0 | BLOQ | NA
| | 1.25 | 1.24 ± 0.01 | −0.8
| | 2.7 | 2.7 ± 0.04 | 0.0
| | 5.8 | 5.84 ± 0.06 | 0.7
| | 12.5 | 12.5 ± 0.05 | 0.0
June 15, 2015 | June 17, 2015 | 0 | BLOQ | NA
| | 1.25 | 1.27 ± 0.02 | 1.6
| | 2.7 | 2.7 ± 0.07 | 0.0
| | 5.8 | 5.71 ± 0.04 | −1.6
| | 12.5 | 12.1 ± 0.4 | −3.2
July 20, 2015 | July 24, 2015 | 0 | BLOQ | NA
| | 1.25 | 1.20 ± 0.01 | −4.0
| | 2.7 | 2.54 ± 0.02 | −5.9
| | 5.8 | 5.58 ± 0.04 | −3.8
| | 12.5 | 12.0 ± 0.3 | −4.0
August 24, 2015 | August 27, 2015 | 0 | BLOQ | NA
| | 1.25 | 1.19 ± 0.01 | −4.8
| | 2.7 | 2.61 ± 0.04 | −3.3
| | 5.8 | 5.62 ± 0.08 | −3.1
| | 12.5 | 12.3 ± 0.2 | −1.6

BLOQ = below the limit of quantification; NA = not applicable.

^a^ Data are presented as mean ± standard deviation.

^b^ Prepared on February 21, 2014.

Figure A-1

^1^H Nuclear Magnetic Resonance Spectrum of Triclosan

Figure A-2

^1^H Nuclear Magnetic Resonance Spectrum of Ethanol