# Overview

Botanical dietary supplements, sometimes called herbals or herbal dietary supplements, are products made from plants. National Toxicology Program (NTP) research has contributed to the field of botanical product safety evaluation by reporting hazard characterization of many botanical dietary supplements and supporting development of strategies for their efficient and effective evaluation.

Black cohosh, a perennial species of buttercup, is used to make botanical dietary supplements primarily sold to aid female gynecological symptoms. Because of its widespread use and the lack of safety data, the effects of black cohosh have been thoroughly studied as part of a broad NTP research program.^1^ Subchronic studies in female rats and mice demonstrated potential genotoxic and developmental effects. The mechanisms behind these findings were investigated in a follow-up mouse study and in vitro genetic toxicology studies.^2^ Potential reproductive and developmental toxicity was further evaluated in rats using a Reproductive Assessment by Continuous Breeding (RACB) study. This report details studies of potential chronic toxicity and carcinogenic activity that were conducted in rats and mice due to concern about long-term use and the genotoxicity findings. Of note, the black cohosh root extract test article used in many of these studies was from the same lot and/or supplier, reducing inherent test article variability and allowing for comparisons and extrapolations across studies.