# Publication Details

Publisher: National Toxicology Program

Publishing Location: Research Triangle Park, NC

ISSN: 2378-8925

DOI: https://doi.org/10.22427/NTP-TR-603

Report Series: NTP Technical Report Series

Report Series Number: 603

Official citation: National Toxicology Program (NTP). 2023. NTP technical report on the toxicology and carcinogenesis studies of black cohosh root extract (CASRN 84776-26-1) administered by gavage to Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) rats and female B6C3F1/N mice. Research Triangle Park, NC: National Toxicology Program. Technical Report 603.