# Peer Review

The National Toxicology Program (NTP) conducted a peer review of the draft NTP Technical Report on the Toxicology and Carcinogenesis Studies of Black Cohosh Root Extract (CASRN 84776-26-1) Administered by Gavage to Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) Rats and Female B6C3F1/N Mice by letter in January 2023 by the experts listed below. Reviewer selection and document review followed established NTP practices. The reviewers were charged to:

1. Peer review the draft NTP Technical Report on the Toxicology and Carcinogenesis Studies of Black Cohosh Root Extract (CASRN 84776-26-1) Administered by Gavage to Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) Rats and Female B6C3F1/N Mice
2. Comment on NTP’s interpretations of the data.

NTP carefully considered reviewer comments in finalizing this report.

## Peer Reviewers

- Nathaniel Collins, D.V.M., Ph.D.
  Vice President, Nonclinical Safety Portfolio Leadership
  Bristol Myers Squibb
  Summit, New Jersey, USA
- Lee Geiger, Ph.D.
  Principal
  Geiger Toxicology Consulting LLC
  Annapolis, Maryland, USA
- Padhma Ranganathan, Ph.D.
  Senior Manager
  Ingredion, Inc.
  New York City, New York, USA
- Richard van Breemen, Ph.D.
  Professor of Pharmaceutical Sciences, College of Pharmacy
  Oregon State University
  Corvallis, Oregon, USA