# Collaborators

- Division of Translational Toxicology, National Institute of Environmental Health Sciences, Research Triangle Park, North Carolina, USA
  Designed studies, evaluated and interpreted results, and reported findings
  C.R. Blystone, Ph.D., Co-study Scientist
  M.C. Huang, Ph.D., Co-study Scientist
  M.F. Cesta, D.V.M., Ph.D.
  M.C. Cora, D.V.M.
  H.C. Cunny, Ph.D.
  M.J. Hooth, Ph.D.
  A.P. King-Herbert, D.V.M.
  D.E. Malarkey, D.V.M., Ph.D. (Retired)
  B.S. McIntyre, Ph.D.
  E. Mutlu, Ph.D.
  G.K. Roberts, Ph.D.
  K.A. Shipkowski, Ph.D.
  K.R. Shockley, Ph.D.
  S.L. Smith-Roe, Ph.D.
  M.D. Stout, Ph.D.
  S. Waidyanatha, Ph.D.
  N.J. Walker, Ph.D.
  K.L. Witt, M.S. (Retired)
- Provided oversight for data management
  J.M. Fostel, Ph.D.
- Experimental Pathology Laboratories, Inc., Research Triangle Park, North Carolina, USA
  Evaluated and interpreted results and reported findings
  A.E. Brix, D.V.M., Ph.D., Study Pathologist
- Battelle, Columbus, Ohio, USA
  Conducted studies and evaluated pathology findings
  M.R. Hejtmancik, Ph.D., Principal Investigator
  B.R. Sparrow, Ph.D., Principal Investigator
  T.P. Arndt, Ph.D.
  K.E. Elsass, B.S.
  C.A. Granville, Ph.D.
  S.J. Harbo, D.V.M.
  K.A.B. Knostman, D.V.M., Ph.D.
  A.J. Skowronek, D.V.M., Ph.D.
- Conducted prestart chemistry activities and dose formulations
  B.L. Burback, Ph.D., Principal Investigator
  S.W. Graves, B.S., Principal Investigator
  J.C. Andre, Ph.D.
  W.M. Black, B.S.
  D.B. Browning, B.S.
  D.A. Contos, M.S.
  T.A. Cristy, B.A.
  R.E. Haney, M.S.
  J. Pierfelice, B.S.
  J.S. Richey, M.S.
- Charles River Laboratories, Inc., Durham, North Carolina, USA
  Provided pathology review
  V.S. Chen, D.V.M., Ph.D.
  Q.D. Plumlee, D.V.M.
- Coordinated Pathology Working Group on 2-year rats (December 10, 2019) and 3- and 12-month and 2-year female mice (February 18, 2020)
  V.S. Chen, D.V.M., Ph.D. (Mice)
  Q.D. Plumlee, D.V.M. (Rats)
- Coordinated Pathology Peer Review on kidney step sections of 2-year rats (December 11 and 13, 2019)
  Q.D. Plumlee, D.V.M.
- ICF, Reston, Virginia, USA
  Contributed to technical writing and data integration and ensured report quality
  K.E. Setty, Ph.D.
  J.W. Tracy, M.H.S.