# References

1 National Toxicology Program (NTP). Testing status of black cohosh M000058. Chemical Effects in Biological Systems (CEBS). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Toxicology Program. [Accessed: 2021]. https://ntp.niehs.nih.gov/go/ts-m000058
2 Cora MC, Gwinn W, Wilson R, King D, Waidyanatha S, Kissling GE, Brar SS, Olivera D, Blystone C, Travlos G. A black cohosh extract causes hematologic and biochemical changes consistent with a functional cobalamin deficiency in female B6C3F1/N mice. Toxicol Pathol. 2017; 45(5):614–623. 10.1177/0192623317714343 28618975
3 King J, Felter HW, Lloyd JU. King’s American dispensatory. Vol. 1. 19th ed., 4th rev. Cincinnati, OH: Ohio Valley Co.; 1909.
4 Foster S, Tyler VE. Black cohosh. In: Tyler’s Honest Herbal: A Sensible Guide to the Use of Herbs and Related Remedies. 4th ed. Binghamton, NY: Haworth Herbal Press; 1999. p. 51–54. 10.4324/9780203819692
5 Budavari S. The Merck index. 12th ed. Whitehouse Station, NJ: Merck & Co.; 1996.
6 Blumenthal M, Busse WR, Goldberg A, Gruenwald J, Hall T, Riggins CW, Rister RS. Black cohosh root. In: The Complete German Commission E Monographs: Therapeutic Guide to Herbal Medicines. Austin, TX: American Botanical Council; 1998.
7 Hobbs C. Menopause and black cohosh. Topeka, KS: Mother Hearth Living; 1998. https://www.motherearthliving.com/health-and-wellness/black-cohosh-a-womans-herb-comes-of-age.
8 Predny ML, De Angelis P, Chamberlain JL. Black cohosh (Actaea racemosa): An annotated bibliography. Asheville, NC: U.S. Department of Agriculture Forest Service, Southern Research Station; 2006. General Technical Report SRS 97. 10.2737/SRS-GTR-97
9 Foster S. Black cohosh: A literature review. HerbalGram. 1999; (45):35–50.
10 Leach MJ, Moore V. Black cohosh (Cimicifuga spp.) for menopausal symptoms. Cochrane Database Syst Rev. 2012; 2012(9):CD007244. 22972105
11 Borrelli F, Ernst E. Black cohosh (Cimicifuga racemosa) for menopausal symptoms: A systematic review of its efficacy. Pharmacol Res. 2008; 58(1):8–14. 10.1016/j.phrs.2008.05.008 18585461
12 Nikolić D, Lankin DC, Cisowska T, Chen SN, Pauli GF, van Breemen RB. Nitrogen-containing constituents of black cohosh: Chemistry, structure elucidation, and biological activities. Recent Adv Phytochem. 2015; 45:31–75. 10.1007/978-3-319-20397-3_2 27795590
13 Einbond LS, Shimizu M, Xiao D, Nuntanakorn P, Lim JT, Suzui M, Seter C, Pertel T, Kennelly EJ, Kronenberg F, et al. Growth inhibitory activity of extracts and purified components of black cohosh on human breast cancer cells. Breast Cancer Res Treat. 2004; 83(3):221–231. 10.1023/B:BREA.0000014043.56230.a3 14758092
14 Burdette JE, Chen SN, Lu ZZ, Xu H, White BE, Fabricant DS, Liu J, Fong HH, Farnsworth NR, Constantinou AI, et al. Black cohosh (Cimicifuga racemosa L.) protects against menadione-induced DNA damage through scavenging of reactive oxygen species: Bioassay-directed isolation and characterization of active principles. J Agric Food Chem. 2002; 50(24):7022–7028. 10.1021/jf020725h 12428954
15 Castleman M, Hendler SS. The healing herbs: The ultimate guide to the curative power of nature’s medicines. Emmaus, PA: Rodale Press; 1991.
16 Lieberman S. A review of the effectiveness of Cimicifuga racemosa (black cohosh) for the symptoms of menopause. J Womens Health. 1998; 7(5):525–529. 10.1089/jwh.1998.7.525 9650153
17 Johnson TL, Fahey JW. Black cohosh: Coming full circle? J Ethnopharmacol. 2012; 141(3):775–779. 10.1016/j.jep.2012.03.050 22504147
18 Gentry-Maharaj A, Karpinskyj C, Glazer C, Burnell M, Ryan A, Fraser L, Lanceley A, Jacobs I, Hunter MS, Menon U. Use and perceived efficacy of complementary and alternative medicines after discontinuation of hormone therapy: A nested United Kingdom Collaborative Trial of Ovarian Cancer Screening cohort study. Menopause. 2015; 22(4):384–390. 10.1097/GME.0000000000000330 25290539
19 World Health Organization (WHO). WHO monographs on selected medicinal plants. Vol. 2. Geneva, Switzerland: World Health Organization; 2002.
20 Allaire AD, Moos MK, Wells SR. Complementary and alternative medicine in pregnancy: A survey of North Carolina certified nurse-midwives. Obstet Gynecol. 2000; 95(1):19–23. 10.1097/00006250-200001000-00004 10636495
21 Bayles BP. Herbal and other complementary medicine use by Texas midwives. J Midwifery Womens Health. 2007; 52(5):473–478. 10.1016/j.jmwh.2007.03.023 17826710
22 Hastings-Tolsma M, Terada M. Complementary medicine use by nurse midwives in the U.S. Complement Ther Clin Pract. 2009; 15(4):212–219. 10.1016/j.ctcp.2009.06.016 19880084
23 Dennehy C, Tsourounis C, Bui L, King TL. The use of herbs by California midwives. J Obstet Gynecol Neonatal Nurs. 2010; 39(6):684–693. 10.1111/j.1552-6909.2010.01193.x 21044150
24 Smith T, May G, Eckl V, Reynolds CM. US sales of herbal supplements increase by 8.6% in 2019. HerbalGram. 2020; (127):54–69.
25 National Institutes of Health (NIH). Dietary Supplement Label Database. Bethesda, MD: National Institutes of Health; 2013–2023. [Accessed: May 2021]. https://dsld.od.nih.gov/dsld/index.jsp
26 Shao Y, Harris A, Wang M, Zhang H, Cordell GA, Bowman M, Lemmo E. Triterpene glycosides from Cimicifuga racemosa. J Nat Prod. 2000; 63(7):905–910. 10.1021/np000047y 10924163
27 Chen SN, Li W, Fabricant DS, Santarsiero BD, Mesecar A, Fitzloff JF, Fong HH, Farnsworth NR. Isolation, structure elucidation, and absolute configuration of 26-deoxyactein from Cimicifuga racemosa and clarification of nomenclature associated with 27-deoxyactein. J Nat Prod. 2002; 65(4):601–605. 10.1021/np010494t 11975513
28 Ruhlen RL, Haubner J, Tracy JK, Zhu W, Ehya H, Lamberson WR, Rottinghaus GE, Sauter ER. Black cohosh does not exert an estrogenic effect on the breast. Nutr Cancer. 2007; 59(2):269–277. 10.1080/01635580701506968 18001221
29 Ruhlen RL, Sun GY, Sauter ER. Black cohosh: Insights into its mechanism(s) of action. Integr Med Insights. 2008; 3:21–32. 10.4137/117863370800300002 21614156
30 Drugs.com. Remifemin menopause tablets. Dallas, TX: Drugs.com; 2001–2023. [Accessed: 2021]. https://www.drugs.com/drp/remifemin-menopause-tablets.html
31 Jiang B, Kronenberg F, Nuntanakorn P, Qiu MH, Kennelly EJ. Evaluation of the botanical authenticity and phytochemical profile of black cohosh products by high-performance liquid chromatography with selected ion monitoring liquid chromatography-mass spectrometry. J Agric Food Chem. 2006; 54(9):3242–3253. 10.1021/jf0606149 16637680
32 Ryan KR, Huang MC, Ferguson SS, Waidyanatha S, Ramaiahgari S, Rice JR, Dunlap PE, Auerbach SS, Mutlu E, Cristy T, et al. Evaluating sufficient similarity of botanical dietary supplements: Combining chemical and in vitro biological data. Toxicol Sci. 2019; 172(2):316–329. 10.1093/toxsci/kfz189 31504990
33 Franco OH, Chowdhury R, Troup J, Voortman T, Kunutsor S, Kavousi M, Oliver-Williams C, Muka T. Use of plant-based therapies and menopausal symptoms: A systematic review and meta-analysis. JAMA. 2016; 315(23):2554–2563. 10.1001/jama.2016.8012 27327802
34 Schaper & Brümmer. Remifemin: Package leaflet: Information for the user. Salzgitter, Germany: Schaper & Brümmer GmbH & Co. KG; 2019. https://www.schaper-bruemmer.com/fileadmin/docs/leaflets/Information_Remifemin_Tabletten.pdf
35 Waidyanatha S, Ryan K, Roe AL, Jia W, Paine MF, Ferguson S, Gurley BJ, Welch K, Chow MSS, Devito M, et al. Follow that botanical: Challenges and recommendations for assessing absorption, distribution, metabolism and excretion of botanical dietary supplements. Food Chem Toxicol. 2018; 121:194–202. 10.1016/j.fct.2018.08.062 30170118
36 ConsumerLab.com. Menopause supplements review (soy and red clover isoflavones, black cohosh) and progesterone creams. White Plains, NY: ConsumerLab.com; 2015–2023. [Accessed: 2020]. https://www.consumerlab.com/reviews/soy-isoflavones-red-clover-black-cohosh-supplements/phytoestrogens/
37 Shoemaker S. Black cohosh: Benefits, dosage, side effects, and more. New York, NY: Healthline; 2020. https://www.healthline.com/health/food-nutrition/black-cohosh.
38 Dietary Supplement Health and Education Act of 1994, Public Law No. 103-417, 103rd Congress.
39 Croom EM, Walker L. Botanicals in the pharmacy: New life for old remedies. Drug Top. 1995; 139(6):84–93.
40 Committee on Herbal Medicinal Products (HMPC). European Union herbal monograph on Cimicifuga racemosa (L.) Nutt., rhizoma. London, UK: European Medicines Agency; 2018. EMA/HMPC/48745/2017.
41 Pang X, Cheng J, Krausz KW, Guo DA, Gonzalez FJ. Pregnane X receptor-mediated induction of Cyp3a by black cohosh. Xenobiotica. 2011; 41(2):112–123. 10.3109/00498254.2010.527021 20979450
42 Einbond LS, Soffritti M, Esposti DD, Park T, Cruz E, Su T, Wu HA, Wang X, Zhang YJ, Ham J, et al. Actein activates stress- and statin-associated responses and is bioavailable in Sprague-Dawley rats. Fundam Clin Pharmacol. 2009; 23(3):311–321. 10.1111/j.1472-8206.2009.00673.x 19527300
43 van Breemen RB, Liang W, Banuvar S, Shulman LP, Pang Y, Tao Y, Nikolic D, Krock KM, Fabricant DS, Chen SN, et al. Pharmacokinetics of 23-epi-26-deoxyactein in women after oral administration of a standardized extract of black cohosh. Clin Pharmacol Ther. 2010; 87(2):219–225. 10.1038/clpt.2009.251 20032972
44 Wanwimolruk S, Wong K, Wanwimolruk P. Variable inhibitory effect of different brands of commercial herbal supplements on human cytochrome P-450 CYP3A4. Drug Metabol Drug Interact. 2009; 24(1):17–35. 10.1515/DMDI.2009.24.1.17 19353999
45 Gurley B, Hubbard MA, Williams DK, Thaden J, Tong Y, Gentry WB, Breen P, Carrier DJ, Cheboyina S. Assessing the clinical significance of botanical supplementation on human cytochrome P450 3A activity: Comparison of a milk thistle and black cohosh product to rifampin and clarithromycin. J Clin Pharmacol. 2006; 46(2):201–213. 10.1177/0091270005284854 16432272
46 Mohamed MF, Tseng T, Frye RF. Inhibitory effects of commonly used herbal extracts on UGT1A1 enzyme activity. Xenobiotica. 2010; 40(10):663–669. 10.3109/00498254.2010.505669 20666626
47 Mohamed ME, Frye RF. Inhibitory effects of commonly used herbal extracts on UDP-glucuronosyltransferase 1A4, 1A6, and 1A9 enzyme activities. Drug Metab Dispos. 2011; 39(9):1522–1528. 10.1124/dmd.111.039602 21632963
48 Gurley BJ, Barone GW, Williams DK, Carrier J, Breen P, Yates CR, Song PF, Hubbard MA, Tong Y, Cheboyina S. Effect of milk thistle (Silybum marianum) and black cohosh (Cimicifuga racemosa) supplementation on digoxin pharmacokinetics in humans. Drug Metab Dispos. 2006; 34(1):69–74. 10.1124/dmd.105.006312 16221754
49 Gurley BJ, Swain A, Hubbard MA, Williams DK, Barone G, Hartsfield F, Tong Y, Carrier DJ, Cheboyina S, Battu SK. Clinical assessment of CYP2D6-mediated herb-drug interactions in humans: Effects of milk thistle, black cohosh, goldenseal, kava kava, St. John’s wort, and echinacea. Mol Nutr Food Res. 2008; 52(7):755–763. 10.1002/mnfr.200600300 18214849
50 Gurley BJ, Gardner SF, Hubbard MA, Williams DK, Gentry WB, Khan IA, Shah A. In vivo effects of goldenseal, kava kava, black cohosh, and valerian on human cytochrome P450 1A2, 2D6, 2E1, and 3A4/5 phenotypes. Clin Pharmacol Ther. 2005; 77(5):415–426. 10.1016/j.clpt.2005.01.009 15900287
51 Tsukamoto S, Aburatani M, Ohta T. Isolation of CYP3A4 inhibitors from the black cohosh (Cimicifuga racemosa). Evid Based Complement Alternat Med. 2005; 2(2):223–226. 10.1093/ecam/neh086 15937564
52 Huang Y, Jiang B, Nuntanakorn P, Kennelly EJ, Shord S, Lawal TO, Mahady GB. Fukinolic acid derivatives and triterpene glycosides from black cohosh inhibit CYP isozymes, but are not cytotoxic to Hep-G2 cells in vitro. Curr Drug Saf. 2010; 5(2):118–124. 10.2174/157488610790936150 20406160
53 Sevior DK, Hokkanen J, Tolonen A, Abass K, Tursas L, Pelkonen O, Ahokas JT. Rapid screening of commercially available herbal products for the inhibition of major human hepatic cytochrome P450 enzymes using the N-in-one cocktail. Xenobiotica. 2010; 40(4):245–254. 10.3109/00498251003592683 20218935
54 Shi S, Klotz U. Drug interactions with herbal medicines. Clin Pharmacokinet. 2012; 51(2):77–104. 10.2165/11597910-000000000-00000 22257149
55 Mercado-Feliciano M, Cora MC, Witt KL, Granville CA, Hejtmancik MR, Fomby L, Knostman KA, Ryan MJ, Newbold R, Smith C, et al. An ethanolic extract of black cohosh causes hematological changes but not estrogenic effects in female rodents. Toxicol Appl Pharmacol. 2012; 263(2):138–147. 10.1016/j.taap.2012.05.022 22687605
56 Lüde S, Török M, Dieterle S, Knapp AC, Kaeufeler R, Jäggi R, Spornitz U, Krähenbühl S. Hepatic effects of Cimicifuga racemosa extract in vivo and in vitro. Cell Mol Life Sci. 2007; 64(21):2848–2857. 10.1007/s00018-007-7368-4 17928951
57 Mazzanti G, Di Sotto A, Franchitto A, Mastrangelo S, Pezzella M, Vitalone A, Mammola CL. Effects of Cimicifuga racemosa extract on liver morphology and hepatic function indices. Phytomedicine. 2008; 15(11):1021–1024. 10.1016/j.phymed.2008.02.023 18434119
58 Huntley A. The safety of black cohosh (Actaea racemosa, Cimicifuga racemosa). Expert Opin Drug Saf. 2004; 3(6):615–623. 10.1517/14740338.3.6.615 15500420
59 Blitz MJ, Smith-Levitin M, Rochelson B. Severe hyponatremia associated with use of black cohosh during prolonged labor and unsuccessful home birth. AJP Rep. 2016; 6(1):e121–e124. 10.1055/s-0036-1579537 26989565
60 Whiting PW, Clouston A, Kerlin P. Black cohosh and other herbal remedies associated with acute hepatitis. Med J Aust. 2002; 177(8):432–435. 10.5694/j.1326-5377.2002.tb04886.x 12381254
61 Levitsky J, Alli TA, Wisecarver J, Sorrell MF. Fulminant liver failure associated with the use of black cohosh. Dig Dis Sci. 2005; 50(3):538–539. 10.1007/s10620-005-2470-7 15810638
62 Chow ECY, Teo M, Ring JA, Chen JW. Liver failure associated with the use of black cohosh for menopausal symptoms. Med J Aust. 2008; 188(7):420–422. 10.5694/j.1326-5377.2008.tb01691.x 18393750
63 Mahady GB, Low Dog T, Barrett ML, Chavez ML, Gardiner P, Ko R, Marles RJ, Pellicore LS, Giancaspro GI, Sarma DN. United States Pharmacopeia review of the black cohosh case reports of hepatotoxicity. Menopause. 2008; 15(4):628–638. 10.1097/gme.0b013e31816054bf 18340277
64 Teschke R. Black cohosh and suspected hepatotoxicity: Inconsistencies, confounding variables, and prospective use of a diagnostic causality algorithm. A critical review. Menopause. 2010; 17(2):426–440. 10.1097/gme.0b013e3181c5159c 20216279
65 Naser B, Schnitker J, Minkin MJ, de Arriba SG, Nolte KU, Osmers R. Suspected black cohosh hepatotoxicity: No evidence by meta-analysis of randomized controlled clinical trials for isopropanolic black cohosh extract. Menopause. 2011; 18(4):366–375. 10.1097/gme.0b013e3181fcb2a6 21228727
66 Shipkowski KA, Betz JM, Birnbaum LS, Bucher JR, Coates PM, Hopp DC, MacKay D, Oketch-Rabah H, Walker NJ, Welch C, et al. Naturally complex: Perspectives and challenges associated with botanical dietary supplement safety assessment. Food Chem Toxicol. 2018; 118:963–971. 10.1016/j.fct.2018.04.007 29626579
67 Piersen CE. Phytoestrogens in botanical dietary supplements: Implications for cancer. Integr Cancer Ther. 2003; 2(2):120–138. 10.1177/1534735403002002004 15035899
68 Jarry H, Harnischfeger G, Düker E. Studies on the endocrine effects of the contents of Cimicifuga racemosa 2. In vitro binding of compounds to estrogen receptors. Planta Med. 1985; 51(4):316–319. 10.1055/s-2007-969500 17340522
69 Jarry H, Metten M, Spengler B, Christoffel V, Wuttke W. In vitro effects of the Cimicifuga racemosa extract BNO 1055. Maturitas. 2003; 44 Suppl 1:S31–S38. 10.1016/S0378-5122(02)00346-8 12609557
70 Düker EM, Kopanski L, Jarry H, Wuttke W. Effects of extracts from Cimicifuga racemosa on gonadotropin release in menopausal women and ovariectomized rats. Planta Med. 1991; 57(5):420–424. 10.1055/s-2006-960139 1798794
71 Liu J, Burdette JE, Xu H, Gu C, van Breemen RB, Bhat KP, Booth N, Constantinou AI, Pezzuto JM, Fong HH, et al. Evaluation of estrogenic activity of plant extracts for the potential treatment of menopausal symptoms. J Agric Food Chem. 2001; 49(5):2472–2479. 10.1021/jf0014157 11368622
72 Onorato J, Henion JD. Evaluation of triterpene glycoside estrogenic activity using LC/MS and immunoaffinity extraction. Anal Chem. 2001; 73(19):4704–4710. 10.1021/ac010409m 11605850
73 Kretzschmar G, Nisslein T, Zierau O, Vollmer G. No estrogen-like effects of an isopropanolic extract of Rhizoma Cimicifugae racemosae on uterus and vena cava of rats after 17 day treatment. J Steroid Biochem Mol Biol. 2005; 97(3):271–277. 10.1016/j.jsbmb.2005.05.008 16191479
74 Seidlová-Wuttke D, Jarry H, Becker T, Christoffel V, Wuttke W. Pharmacology of Cimicifuga racemosa extract BNO 1055 in rats: Bone, fat and uterus. Maturitas. 2003; 44 Suppl 1:S39–S50. 10.1016/S0378-5122(02)00347-X 12609558
75 Rachoń D, Vortherms T, Seidlová-Wuttke D, Wuttke W. Effects of black cohosh extract on body weight gain, intra-abdominal fat accumulation, plasma lipids and glucose tolerance in ovariectomized Sprague-Dawley rats. Maturitas. 2008; 60(3-4):209–215. 10.1016/j.maturitas.2008.06.001 18691839
76 Nißlein T, Freudenstein J. Effects of an isopropanolic extract of Cimicifuga racemosa on urinary crosslinks and other parameters of bone quality in an ovariectomized rat model of osteoporosis. J Bone Miner Metab. 2003; 21(6):370–376. 10.1007/s00774-003-0431-9 14586793
77 Burdette JE, Liu J, Chen SN, Fabricant DS, Piersen CE, Barker EL, Pezzuto JM, Mesecar A, Van Breemen RB, Farnsworth NR, et al. Black cohosh acts as a mixed competitive ligand and partial agonist of the serotonin receptor. J Agric Food Chem. 2003; 51(19):5661–5670. 10.1021/jf034264r 12952416
78 Bodinet C, Freudenstein J. Influence of Cimicifuga racemosa on the proliferation of estrogen receptor-positive human breast cancer cells. Breast Cancer Res Treat. 2002; 76(1):1–10. 10.1023/A:1020241509382 12408370
79 Hostanska K, Nisslein T, Freudenstein J, Reichling J, Saller R. Cimicifuga racemosa extract inhibits proliferation of estrogen receptor-positive and negative human breast carcinoma cell lines by induction of apoptosis. Breast Cancer Res Treat. 2004; 84(2):151–160. 10.1023/B:BREA.0000018413.98636.80 14999145
80 Jarry H, Thelen P, Christoffel V, Spengler B, Wuttke W. Cimicifuga racemosa extract BNO 1055 inhibits proliferation of the human prostate cancer cell line LNCaP. Phytomedicine. 2005; 12(3):178–182. 10.1016/j.phymed.2004.02.006 15830838
81 Viereck V, Gründker C, Friess SC, Frosch KH, Raddatz D, Schoppet M, Nisslein T, Emons G, Hofbauer LC. Isopropanolic extract of black cohosh stimulates osteoprotegerin production by human osteoblasts. J Bone Miner Res. 2005; 20(11):2036–2043. 10.1359/JBMR.050716 16234977
82 Wuttke W, Jarry H, Haunschild J, Stecher G, Schuh M, Seidlová-Wuttke D. The non-estrogenic alternative for the treatment of climacteric complaints: Black cohosh (Cimicifuga or Actaea racemosa). J Steroid Biochem Mol Biol. 2014; 139:302–310. 10.1016/j.jsbmb.2013.02.007 23459142
83 Rauš K, Brucker C, Gorkow C, Wuttke W. First-time proof of endometrial safety of the special black cohosh extract (Actaea or Cimicifuga racemosa extract) CR BNO 1055. Menopause. 2006; 13(4):678–691. 10.1097/01.gme.0000196813.34247.e2 16837890
84 Reed SD, Newton KM, LaCroix AZ, Grothaus LC, Grieco VS, Ehrlich K. Vaginal, endometrial, and reproductive hormone findings: Randomized, placebo-controlled trial of black cohosh, multibotanical herbs, and dietary soy for vasomotor symptoms: The Herbal Alternatives for Menopause (HALT) Study. Menopause. 2008; 15(1):51–58. 10.1097/gme.0b013e318057787f 18257142
85 Nappi RE, Malavasi B, Brundu B, Facchinetti F. Efficacy of Cimicifuga racemosa on climacteric complaints: A randomized study versus low-dose transdermal estradiol. Gynecol Endocrinol. 2005; 20(1):30–35. 10.1080/09513590400020922 15969244
86 Reame NE, Lukacs JL, Padmanabhan V, Eyvazzadeh AD, Smith YR, Zubieta JK. Black cohosh has central opioid activity in postmenopausal women: Evidence from naloxone blockade and positron emission tomography neuroimaging. Menopause. 2008; 15(5):832–840. 10.1097/gme.0b013e318169332a 18521048
87 Jacobson JS, Troxel AB, Evans J, Klaus L, Vahdat L, Kinne D, Lo KM, Moore A, Rosenman PJ, Kaufman EL, et al. Randomized trial of black cohosh for the treatment of hot flashes among women with a history of breast cancer. J Clin Oncol. 2001; 19(10):2739–2745. 10.1200/JCO.2001.19.10.2739 11352967
88 Wang C, Huang Q, Liang CL, Zhang YW, Deng DH, Yu Y, Chen DB, Yang HJ, Yu XF. Effect of Cimicifuga racemosa on menopausal syndrome caused by LHRH-a in breast cancer. J Ethnopharmacol. 2019; 238:111840. 10.1016/j.jep.2019.111840 30935866
89 Liske E, Hänggi W, Henneicke-von Zepelin HH, Boblitz N, Wüstenberg P, Rahlfs VW. Physiological investigation of a unique extract of black cohosh (Cimicifugae racemosae rhizoma): A 6-month clinical study demonstrates no systemic estrogenic effect. J Womens Health Gend Based Med. 2002; 11(2):163–174. 10.1089/152460902753645308 11975864
90 Stoll W. [ Phytopharmacon influences atrophic vaginal epithelium: Double blind study: Cimicifuga vs. estrogenic substances ]. Therapeutikon. 1987; 1:23–31.
91 Schmid D, Woehs F, Svoboda M, Thalhammer T, Chiba P, Moeslinger T. Aqueous extracts of Cimicifuga racemosa and phenolcarboxylic constituents inhibit production of proinflammatory cytokines in LPS-stimulated human whole blood. Can J Physiol Pharmacol. 2009; 87(11):963–972. 10.1139/Y09-091 19935904
92 Yang CL, Chik SC, Li JC, Cheung BK, Lau AS. Identification of the bioactive constituent and its mechanisms of action in mediating the anti-inflammatory effects of black cohosh and related Cimicifuga species on human primary blood macrophages. J Med Chem. 2009; 52(21):6707–6715. 10.1021/jm9006164 19835377
93 Kim CD, Lee WK, Lee MH, Cho HS, Lee YK, Roh SS. Inhibition of mast cell-dependent allergy reaction by extract of black cohosh (Cimicifuga racemosa). Immunopharmacol Immunotoxicol. 2004; 26(2):299–308. 10.1081/IPH-120037728 15209365
94 Schmid D, Gruber M, Woehs F, Prinz S, Etzlstorfer B, Prucker C, Fuzzati N, Kopp B, Moeslinger T. Inhibition of inducible nitric oxide synthesis by Cimicifuga racemosa (Actaea racemosa, black cohosh) extracts in LPS-stimulated RAW 264.7 macrophages. J Pharm Pharmacol. 2009; 61(8):1089–1096. 10.1211/jpp/61.08.0013 19703353
95 Smith MJ, Germolec DR, Frawley RP, White KL Jr. Immunomodulatory effects of black cohosh (Actaea racemosa) extract in female B6C3F1/N mice. Toxicology. 2013; 308:146–157. 10.1016/j.tox.2013.03.017 23571075
96 Hirabayashi T, Ochiai H, Sakai S, Nakajima K, Terasawa K. Inhibitory effect of ferulic acid and isoferulic acid on murine interleukin-8 production in response to influenza virus infections in vitro and in vivo. Planta Med. 1995; 61(3):221–226. 10.1055/s-2006-958060 7617763
97 Hirata A, Murakami Y, Atsumi T, Shoji M, Ogiwara T, Shibuya K, Ito S, Yokoe I, Fujisawa S. Ferulic acid dimer inhibits lipopolysaccharide-stimulated cyclooxygenase-2 expression in macrophages. In Vivo. 2005; 19(5):849–853. 16097437
98 Chawla AS, Singh M, Murthy MS, Gupta M, Singh H. Anti-inflammatory action of ferulic acid and its esters in carrageenan induced rat paw oedema model. Indian J Exp Biol. 1987; 25(3):187–189. 3666817
99 Hemmi H, Ishida N. The immune response of splenic lymphocytes after cimicifugoside treatment in vitro and pretreatment in vivo. J Pharmacobiodyn. 1980; 3(12):643–648. 10.1248/bpb1978.3.643 7277179
100 Hemmi H, Kitame F, Ishida N, Kusano G, Kondo Y, Nozoe S. Inhibition of thymidine transport into phytohemagglutinin-stimulated lymphocytes by triterpenoids from Cimicifuga species. J Pharmacobiodyn. 1979; 2(6):339–349. 10.1248/bpb1978.2.339
101 Qiu M, Kim JH, Lee HK, Min BS. Anticomplement activity of cycloartane glycosides from the rhizome of Cimicifuga foetida. Phytother Res. 2006; 20(11):945–948. 10.1002/ptr.1982 16906637
102 Pan RL, Chen DH, Si JY, Zhao XH, Li Z, Cao L. Immunosuppressive effects of new cyclolanostane triterpene diglycosides from the aerial part of Cimicifuga foetida. Arch Pharm Res. 2009; 32(2):185–190. 10.1007/s12272-009-1133-1 19280146
103 Nishida M, Yoshimitsu H, Nohara T. Three cycloartane glycosides from Cimicifuga rhizome and their immunosuppressive activities in mouse allogeneic mixed lymphocyte reaction. Chem Pharm Bull (Tokyo). 2003; 51(3):354–356. 10.1248/cpb.51.354 12612431
104 Su Y, Wu L, Mu G, Wang Q, Yang B, Cheng G, Kuang H. 9,19-Cycloartenol glycoside G3 from Cimicifuga simplex regulates immune responses by modulating Th17/Treg ratio. Bioorg Med Chem. 2017; 25(17):4917–4923. 10.1016/j.bmc.2017.07.042 28780985
105 Einbond LS, Soffritti M, Degli Esposti D, Tibaldi E, Lauriola M, Bua L, He K, Genovese G, Su T, Huggins L, et al. Chemopreventive potential of black cohosh on breast cancer in Sprague-Dawley rats. Anticancer Res. 2012; 32(1):21–30. 22213284
106 Davis VL, Jayo MJ, Ho A, Kotlarczyk MP, Hardy ML, Foster WG, Hughes CL. Black cohosh increases metastatic mammary cancer in transgenic mice expressing c-erbB2. Cancer Res. 2008; 68(20):8377–8383. 10.1158/0008-5472.CAN-08-1812 18922910
107 Nißlein T, Freudenstein J. Concomitant administration of an isopropanolic extract of black cohosh and tamoxifen in the in vivo tumor model of implanted RUCA-I rat endometrial adenocarcinoma cells. Toxicol Lett. 2004; 150(3):271–275. 10.1016/j.toxlet.2004.02.006 15110078
108 Seidlová-Wuttke D, Thelen P, Wuttke W. Inhibitory effects of a black cohosh (Cimicifuga racemosa) extract on prostate cancer. Planta Med. 2006; 72(6):521–526. 10.1055/s-2006-931538 16773536
109 Fritz H, Seely D, McGowan J, Skidmore B, Fernandes R, Kennedy DA, Cooley K, Wong R, Sagar S, Balneaves LG, et al. Black cohosh and breast cancer: A systematic review. Integr Cancer Ther. 2014; 13(1):12–29. 10.1177/1534735413477191 23439657
110 McGrowder DA, Miller FG, Nwokocha CR, Anderson MS, Wilson-Clarke C, Vaz K, Anderson-Jackson L, Brown J. Medicinal herbs used in traditional management of breast cancer: Mechanisms of action. Medicines (Basel). 2020; 7(8):47. 10.3390/medicines7080047 32823812
111 Einbond LS, Soffritti M, Esposti DD, Wu HA, Tibaldi E, Lauriola M, He K, Park T, Su T, Huggins L, et al. Pharmacological mechanisms of black cohosh in Sprague-Dawley rats. Fitoterapia. 2012; 83(3):461–468. 10.1016/j.fitote.2011.12.011 22198559
112 Einbond LS, Soffritti M, Esposti DD, Wu HA, Balick M, Ma H, Redenti S, Roter A. A transcriptomic analysis of black cohosh: Actein alters cholesterol biosynthesis pathways and synergizes with simvastatin. Food Chem Toxicol. 2018; 120:356–366. 10.1016/j.fct.2018.06.064 29969672
113 Hostanska K, Nisslein T, Freudenstein J, Reichling J, Saller R. Apoptosis of human prostate androgen-dependent and -independent carcinoma cells induced by an isopropanolic extract of black cohosh involves degradation of cytokeratin (CK) 18. Anticancer Res. 2005; 25 1a:139–147. 15816531
114 Smith-Roe SL, Swartz CD, Shepard KG, Bryce SM, Dertinger SD, Waidyanatha S, Kissling GE, Auerbach SS, Witt KL. Black cohosh extracts and powders induce micronuclei, a biomarker of genetic damage, in human cells. Environ Mol Mutagen. 2018; 59(5):416–426. 10.1002/em.22182 29668046
115 Bernacki DT, Bryce SM, Bemis JC, Dertinger SD, Witt KL, Smith-Roe SL. Evidence for an aneugenic mechanism of action for micronucleus induction by black cohosh extract. Environ Mol Mutagen. 2019; 60(9):845–856. 10.1002/em.22334 31569270
116 Seo JE, Guo X, Petibone DM, Shelton SD, Chen Y, Li X, Tryndyak V, Smith-Roe SL, Witt KL, Mei N, et al. Mechanistic evaluation of black cohosh extract-induced genotoxicity in human cells. Toxicol Sci. 2021; 182(1):96–106. 10.1093/toxsci/kfab044 33856461
117 National Toxicology Program (NTP). Black cohosh extracts and powders induce micronuclei, a biomarker of genetic damage, in human cells. Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Toxicology Program; 2018. [Accessed: 2020]. 10.22427/NTP-DATA-002-01731-0030-0000-7
118 Bonassi S, El-Zein R, Bolognesi C, Fenech M. Micronuclei frequency in peripheral blood lymphocytes and cancer risk: Evidence from human studies. Mutagenesis. 2011; 26(1):93–100. 10.1093/mutage/geq075 21164188
119 NSF International; American National Standards Institute (ANSI). NSF International standard / American national standard for dietary supplements—Dietary supplements. Ann Arbor, MI: NSF International; 2020. NSF/ANSI 173 - 2020. https://webstore.ansi.org/preview-pages/NSF/preview_NSF+ANSI+173-2020.pdf
120 American Herbal Products Association (AHPA). Heavy metals: Analysis and limits in herbal dietary supplements. Silver Spring, MD: American Herbal Products Association; 2009.
121 U.S. Environmental Protection Agency (USEPA). Chlorpropham; tolerances for residues, 40 CFR Sect. 180.181. https://www.ecfr.gov/current/title-40/chapter-I/subchapter-E/part-180/subpart-C/section-180.181
122 U.S. Environmental Protection Agency (USEPA). o-Phenylphenol and its sodium salt; tolerances for residues, 40 CFR Sect. 180.129. https://www.ecfr.gov/current/title-40/chapter-I/subchapter-E/part-180/subpart-C/section-180.129
123 Waidyanatha S, Cristy T, Pierfelice J, Andre JC, Burback B, Mutlu E. Working with natural complexity: Selection and characterization of black cohosh root extract for use in toxicology testing. Food Chem Toxicol. 2022; 160:112769. 10.1016/j.fct.2021.112769 34929352
124 Maronpot RR, Boorman GA. Interpretation of rodent hepatocellular proliferative alterations and hepatocellular tumors in chemical safety assessment. Toxicol Pathol. 1982; 10(2):71–78. 10.1177/019262338201000210 28094716
125 Boorman GA, Haseman JK, Waters MD, Hardisty JF, Sills RC. Quality review procedures necessary for rodent pathology databases and toxicogenomic studies: The National Toxicology Program experience. Toxicol Pathol. 2002; 30(1):88–92. 10.1080/01926230252824752 11890481
126 Brix AE, Hardisty JF, McConnell EE. Combining neoplasms for evaluation of rodent carcinogenesis studies. In: Hsu CH, Stedeford T, editors. Cancer Risk Assessment: Chemical Carcinogenesis, Hazard Evaluation, and Risk Quantification. Hoboken, NJ: Wiley; 2010. p. 699–715. 10.1002/9780470622728.ch28
127 Kaplan EL, Meier P. Nonparametric estimation from incomplete observations. J Am Stat Assoc. 1958; 53(282):457–481. 10.1080/01621459.1958.10501452
128 Tarone RE. Tests for trend in life table analysis. Biometrika. 1975; 62(3):679–690. 10.1093/biomet/62.3.679
129 Cox DR. Regression models and life‐tables. J R Stat Soc Series B Stat Methodol. 1972; 34(2):187–202.
130 Bailer AJ, Portier CJ. Effects of treatment-induced mortality and tumor-induced mortality on tests for carcinogenicity in small samples. Biometrics. 1988; 44(2):417–431. 10.2307/2531856 3390507
131 Piegorsch WW, Bailer AJ. Statistics for environmental biology and toxicology: Section 6.3.2. London, UK: Chapman and Hall; 1997.
132 Portier CJ, Bailer AJ. Testing for increased carcinogenicity using a survival-adjusted quantal response test. Fundam Appl Toxicol. 1989; 12(4):731–737. 10.1016/0272-0590(89)90004-3 2744275
133 Portier CJ, Hedges JC, Hoel DG. Age-specific models of mortality and tumor onset for historical control animals in the National Toxicology Program’s carcinogenicity experiments. Cancer Res. 1986; 46(9):4372–4378. 3731095
134 Bieler GS, Williams RL. Ratio estimates, the delta method, and quantal response tests for increased carcinogenicity. Biometrics. 1993; 49(3):793–801. 10.2307/2532200 8241374
135 Nam JM. A simple approximation for calculating sample sizes for detecting linear trend in proportions. Biometrics. 1987; 43(3):701–705. 10.2307/2532006 3663825
136 Rao JNK, Scott AJ. A simple method for the analysis of clustered binary data. Biometrics. 1992; 48(2):577–585. 10.2307/2532311 1637980
137 Fung KY, Krewski D, Rao JNK, Scott AJ. Tests for trend in developmental toxicity experiments with correlated binary data. Risk Anal. 1994; 14(4):639–648. 10.1111/j.1539-6924.1994.tb00277.x 7972964
138 Gart JJ, Chu KC, Tarone RE. Statistical issues in interpretation of chronic bioassay tests for carcinogenicity. J Natl Cancer Inst. 1979; 62(4):957–974. 285297
139 Dixon WJ, Massey FJ. Introduction to statistical analysis. 2nd ed. New York, NY: McGraw-Hill; 1957. 10.2307/2332898
140 Tukey JW. Easy summaries—numerical and graphical. In: Exploratory Data Analysis. Reading, MA: Addison-Wesley; 1977. p. 27–56.
141 Dunnett CW. A multiple comparison procedure for comparing several treatments with a control. J Am Stat Assoc. 1955; 50(272):1096–1121. 10.1080/01621459.1955.10501294
142 Williams DA. A test for differences between treatment means when several dose levels are compared with a zero dose control. Biometrics. 1971; 27(1):103–117. 10.2307/2528930 5547548
143 Williams DA. The comparison of several dose levels with a zero dose control. Biometrics. 1972; 28(2):519–531. 10.2307/2556164 5037867
144 Shirley E. A non-parametric equivalent of Williams’ test for contrasting increasing dose levels of a treatment. Biometrics. 1977; 33(2):386–389. 10.2307/2529789 884197
145 Williams DA. A note on Shirley’s nonparametric test for comparing several dose levels with a zero-doe control. Biometrics. 1986; 42(1):183–186. 10.2307/2531254 3719054
146 Dunn OJ. Multiple comparisons using rank sums. Technometrics. 1964; 6(3):241–252. 10.1080/00401706.1964.10490181
147 Jonckheere AR. A distribution-free k-sample test against ordered alternatives. Biometrika. 1954; 41(1-2):133–145. 10.1093/biomet/41.1-2.133
148 Hsu JC. The factor analytic approach to simultaneous inference in the general linear model. J Comput Graph Stat. 1992; 1(2):151–168.
149 Haseman JK. Value of historical controls in the interpretation of rodent tumor data. Drug Inf J. 1992; 26(2):191–200. 10.1177/009286159202600210
150 Haseman JK, Rao GN. Effects of corn oil, time-related changes, and inter-laboratory variability on tumor occurrence in control Fischer 344 (F344/N) rats. Toxicol Pathol. 1992; 20(1):52–60. 10.1177/019262339202000107 1411131
151 Haseman JK. Data analysis: Statistical analysis and use of historical control data. Regul Toxicol Pharmacol. 1995; 21(1):52–59, discussion 81–86. 10.1006/rtph.1995.1009 7784636
152 U.S. Food and Drug Administration (FDA). 21 CFR Part 58. https://www.accessdata.fda.gov/scripts/cdrh/cfdocs/cfcfr/CFRSearch.cfm?CFRPart=58
153 Miller JA, Miller EC. Ultimate chemical carcinogens as reactive mutagenic electrophiles. In: Hiatt HH, Watson JD, Winsten JA, editors. Origins of Human Cancer. Cold Spring Harbor, NY: Cold Spring Harbor Laboratory; 1977. p. 605–627.
154 Straus DS. Somatic mutation, cellular differentiation, and cancer causation. J Natl Cancer Inst. 1981; 67(2):233–241. 7021938
155 Crawford BD. Perspectives on the somatic mutation model of carcinogenesis. In: Flamm WG, Lorentzen RJ, editors. Mechanisms and Toxicity of Chemical Carcinogens and Mutagens. Princeton, NJ: Princeton Scientific Publishing; 1985. p. 13–59.
156 Ashby J, Tennant RW. Definitive relationships among chemical structure, carcinogenicity and mutagenicity for 301 chemicals tested by the U.S. NTP. Mutat Res. 1991; 257(3):229–306. 10.1016/0165-1110(91)90003-E 1707500
157 Tennant RW, Margolin BH, Shelby MD, Zeiger E, Haseman JK, Spalding J, Caspary W, Resnick M, Stasiewicz S, Anderson B, et al. Prediction of chemical carcinogenicity in rodents from in vitro genetic toxicity assays. Science. 1987; 236(4804):933–941. 10.1126/science.3554512 3554512
158 Zeiger E, Haseman JK, Shelby MD, Margolin BH, Tennant RW, Holden HE. Evaluation of four in vitro genetic toxicity tests for predicting rodent carcinogenicity: Confirmation of earlier results with 41 additional chemicals. Environ Mol Mutagen. 1990; 16 Suppl 18:1–14. 10.1002/em.2850160502 2091921
159 Schmid W. The micronucleus test. Mutat Res. 1975; 31(1):9–15. 10.1016/0165-1161(75)90058-8 48190
160 Heddle JA, Hite M, Kirkhart B, Mavournin K, MacGregor JT, Newell GW, Salamone MF. The induction of micronuclei as a measure of genotoxicity: A report of the U.S. Environmental Protection Agency Gene-Tox Program. Mutat Res. 1983; 123(1):61–118. 10.1016/0165-1110(83)90047-7 6888413
161 Shelby MD, Erexson GL, Hook GJ, Tice RR. Evaluation of a three-exposure mouse bone marrow micronucleus protocol: Results with 49 chemicals. Environ Mol Mutagen. 1993; 21(2):160–179. 10.1002/em.2850210210 8444144
162 Shelby MD, Witt KL. Comparison of results from mouse bone marrow chromosome aberration and micronucleus tests. Environ Mol Mutagen. 1995; 25(4):302–313. 10.1002/em.2850250407 7607185
163 Witt KL, Knapton A, Wehr CM, Hook GJ, Mirsalis J, Shelby MD, MacGregor JT. Micronucleated erythrocyte frequency in peripheral blood of B6C3F(1) mice from short-term, prechronic, and chronic studies of the NTP carcinogenesis bioassay program. Environ Mol Mutagen. 2000; 36(3):163-194. 10.1002/1098-2280(2000)36:3<163::AID-EM1>3.0.CO;2-P
164 National Toxicology Program (NTP). TR-603: Pathology tables, survival and growth curves from NTP long-term and micronucleus studies. Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Toxicology Program; 2023. 10.22427/NTP-DATA-TR-603
165 Haseman JK, Young E, Eustis SL, Hailey JR. Body weight-tumor incidence correlations in long-term rodent carcinogenicity studies. Toxicol Pathol. 1997; 25(3):256–263. 10.1177/019262339702500302 9210256
166 Lee J, Yi S, Kang YE, Kim HW, Joung KH, Sul HJ, Kim KS, Shong M. Morphological and functional changes in the thyroid follicles of the aged murine and humans. J Pathol Transl Med. 2016; 50(6):426–435. 10.4132/jptm.2016.07.19 27737529
167 Lipman RD, Dallal GE, Bronson RT. Lesion biomarkers of aging in B6C3F1 hybrid mice. J Gerontol A Biol Sci Med Sci. 1999; 54(11):B466–B477. 10.1093/gerona/54.11.B466 10619310
168 National Toxicology Program (NTP). Black cohosh (84776-26-1). Chemical Effects in Biological Systems (CEBS). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Toxicology Program. [Accessed: 2020]. 10.22427/NTP-DATA-DTXSID2030857
169 U.S. Food and Drug Administration (FDA). Guidance for industry: Estimating the maximum safe starting dose in initial clincial trials for therapeutics in adult healthy volunteers. Rockville, MD: U.S. Department of Health and Human Services, Food and Drug Administration, Center for Drug Evaluation and Research (CDER); 2005. https://www.fda.gov/media/72309/download
170 Brix AE, Nyska A, Haseman JK, Sells DM, Jokinen MP, Walker NJ. Incidences of selected lesions in control female Harlan Sprague-Dawley rats from two-year studies performed by the National Toxicology Program. Toxicol Pathol. 2005; 33(4):477–483. 10.1080/01926230590961836 16036865
171 Carmel R. Megaloblastic anemias: Disorders of impaired DNA synthesis. In: Greer JP, Arber DA, Glader B, List AF, Means RT Jr, Paraskevas F, Rodgers GM, editors. Wintrobe’s Clinical Hematology. 13th ed. Philadelphia, PA: Lippincott Williams & Wilkins; 2014. p. 927–953.
172 Hesdorffer CS, Longo DL. Drug-induced megaloblastic anemia. N Engl J Med. 2015; 373(17):1649–1658. 10.1056/NEJMra1508861 26488695
173 Savage DG, Lindenbaum J, Stabler SP, Allen RH. Sensitivity of serum methylmalonic acid and total homocysteine determinations for diagnosing cobalamin and folate deficiencies. Am J Med. 1994; 96(3):239–246. 10.1016/0002-9343(94)90149-X 8154512
174 Shane B. Folate and vitamin B12 function. In: Lennarz WJ, Lane MD, editors. Encyclopedia of Biological Chemistry. 2nd ed. San Diego, CA: Academic Press; 2013. p. 324–328. 10.1016/B978-0-12-378630-2.00039-6
175 Koury MJ, Horne DW, Brown ZA, Pietenpol JA, Blount BC, Ames BN, Hard R, Koury ST. Apoptosis of late-stage erythroblasts in megaloblastic anemia: Association with DNA damage and macrocyte production. Blood. 1997; 89(12):4617–4623. 10.1182/blood.V89.12.4617 9192787
176 Elhajouji A, Lukamowicz M, Cammerer Z, Kirsch-Volders M. Potential thresholds for genotoxic effects by micronucleus scoring. Mutagenesis. 2011; 26(1):199–204. 10.1093/mutage/geq089 21164203
177 Leite C, Hoogstraten B. Differential diagnosis of anemia and cancer. CA Cancer J Clin. 1977; 27(2):88–99. 10.3322/canjclin.27.2.88 402990
178 Stopa EG, O’Brien R, Katz M. Effect of colchicine on guinea pig intrinsic factor-vitamin B12 receptor. Gastroenterology. 1979; 76(2):309–314. 10.1016/0016-5085(79)90338-X 759260
179 Bose S, Kalra S, Yammani RR, Ahuja R, Seetharam B. Plasma membrane delivery, endocytosis and turnover of transcobalamin receptor in polarized human intestinal epithelial cells. J Physiol. 2007; 581(2):457–466. 10.1113/jphysiol.2007.129171 17347267
180 National Toxicology Program (NTP). Nonneoplastic lesion atlas: Thyroid gland - follicle - dilation. Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Toxicology Program; 2014–2023. https://ntp.niehs.nih.gov/atlas/nnl/endocrine-system/thyroid-gland/Follicle-Dilation
181 Tahboub R, Arafah BM. Sex steroids and the thyroid. Best Pract Res Clin Endocrinol Metab. 2009; 23(6):769–780. 10.1016/j.beem.2009.06.005 19942152
182 Meija J, Pagliano E, Mester Z. Coordinate swapping in standard addition graphs for analytical chemistry: A simplified path for uncertainty calculation in linear and nonlinear plots. Anal Chem. 2014; 86(17):8563–8567. 10.1021/ac5014749 25099135
183 Zeiger E, Anderson B, Haworth S, Lawlor T, Mortelmans K. Salmonella mutagenicity tests: V. Results from the testing of 311 chemicals. Environ Mol Mutagen. 1992; 19 Suppl 21:2–141. 10.1002/em.2850190603 1541260
184 Witt KL, Livanos E, Kissling GE, Torous DK, Caspary W, Tice RR, Recio L. Comparison of flow cytometry- and microscopy-based methods for measuring micronucleated reticulocyte frequencies in rodents treated with nongenotoxic and genotoxic chemicals. Mutat Res. 2008; 649(1-2):101–113. 10.1016/j.mrgentox.2007.08.004 17869571
185 Kissling GE, Dertinger SD, Hayashi M, MacGregor JT. Sensitivity of the erythrocyte micronucleus assay: Dependence on number of cells scored and inter-animal variability. Mutat Res. 2007; 634(1-2):235–240. 10.1016/j.mrgentox.2007.07.010 17851117