# Conclusions

Under the conditions of these 2-year gavage studies, there was equivocal evidence of carcinogenic activity of black cohosh root extract (BCE) in female Hsd:Sprague Dawley^®^ SD^®^ rats based on marginal increases in the incidence of uterine squamous cell papillomas. There was no evidence of carcinogenic activity of perinatal BCE exposure in male Hsd:Sprague Dawley^®^ SD^®^ rats at maternal doses of 75, 250, or 750 mg/kg/day.

There was no evidence of carcinogenic activity of BCE in female B6C3F1/N mice at doses of 30, 100, 300, or 1,000 mg/kg/day.

Dose-related nonneoplastic lesions were observed in the uterus and ovary in rats and in the liver and thyroid gland in female mice. A significant decrease in litter size was observed in rats.

Interim hematological evaluations and micronucleus assays in female mice showed disruption of normal erythropoiesis and increased frequency of micronucleated erythrocytes at 3 months; at 12 months, the same effects were observed with similar severity and frequency.