# Discussion

Black cohosh herbal supplements, typically made from extracts of roots and rhizomes, are used by women during many stages of life: for treating premenstrual syndrome, for alleviating pain and promoting cervical ripening during pregnancy, and, most commonly, for the management of menopausal symptoms.

Given the widespread use of black cohosh and the lack of safety data regarding long-term use of black cohosh products, a 2-year NTP carcinogenicity study was conducted in rats and mice, administering black cohosh root extract (BCE) via gavage. The dosing paradigms were designed to emulate periods when humans (primarily women) might consume black cohosh products. The human equivalent doses of the BCE doses administered in the present studies, calculated using body surface area conversion factors,^169^ were 12.1, 40.3, and 121 mg BCE/kg body weight/day (mg/kg/day; 726, 2,419, and 7,258 mg/day for a 60-kg person) for the rat doses of 75, 250, and 750 mg/kg/day; they were 2.4, 8.1, 24.4, and 81.3 mg/kg/day (146, 488, 1,463, and 4,878 mg/day for a 60-kg person) for the mouse doses of 30, 100, 300, and 1,000 mg/kg/day. As noted previously, clinical trials have generally evaluated lower doses of 6.5–160 mg/day for 1–12 months in women, although the formulations tested have varied.^10,33^ As black cohosh products are sometimes used during pregnancy, the rat study incorporated perinatal exposure. Female rat offspring continued to be administered BCE during the postweaning period, but male rat offspring were not. Female mice were administered BCE for 2 years starting at 5–6 weeks of age to emulate consumption of black cohosh products at an early age. A combination of nontargeted and targeted chemical analyses was used to confirm the authenticity of the test material, absence of contaminants and adulteration from other cohosh species, and similarity to a popular black cohosh product used by consumers.^123^

In rats, administration of BCE during gestation and lactation led to significant effects around the parturition period, including significant decreases in postnatal day (PND) 1 and PND 4 litter size and decreases in mean body weights of BCE-dosed dams during late gestation and early lactation. Pups appeared to gain less weight with increasing dose, and mean body weights remained lower in the highest exposed or dosed groups compared to the vehicle control groups throughout the postweaning period of the study. The difference in mean body weights between exposed or dosed animals and vehicle control animals did not change greatly during the postweaning period, indicating that body weight gain was likely consistent across groups and that the lower terminal body weight was due to lower pup body weight postweaning. No studies evaluating reproductive toxicological effects in rodents are available for comparison, including any with prenatal exposure to BCE.

The only neoplasms in rats that might have resulted from BCE exposure were the uterine squamous cell papillomas. There was a marginally higher incidence of these rare neoplasms in the mid-dose females at 250 mg/kg/day. These findings were not statistically significant, but historical control data indicate that these uterine neoplasms are rare in rats (1/500). There was a supporting finding for the nonneoplastic lesion of uterine squamous metaplasia, wherein the incidence was significantly increased in the highest dosed group of 750 mg/kg/day compared to the vehicle control group. Squamous metaplasia is a common background finding in the uterus of Sprague Dawley rats.^170^ A robust dose-response relationship was not observed, however, with the uterine neoplasms in the present studies; the incidences in dosed groups compared to vehicle control animals lacked significant pairwise differences or trends. Thus, the marginal increase in the incidence of rare uterine squamous cell papillomas was considered to be equivocal evidence of carcinogenicity in female rats.

In female mice, mean body weights were lower with increasing dose; most dosed groups exceeded a 10% difference from the vehicle control group starting around study day 141. The lack of body weight differences in BCE-dosed animals during the first few months of the study is consistent with the lack of body weight differences observed in a previous 3-month NTP study in B6C3F1/N female mice.^55^ Subsequent differences in mean body weights relative to the vehicle control group suggest lower body weight gains over the course of the study period.

Complete blood count (CBC) results in female mice at 3 months revealed changes in the erythron that were consistent with previous studies^2,55^; these changes persisted at 12 months. Specifically, with increasing dose, there was a decrease in the erythrocyte count and an increase in mean cell volume (MCV; macrocytosis) and mean cell hemoglobin with no change in the reticulocyte count (nonregenerative). In previous NTP BCE studies, increased micronuclei (Howell-Jolly bodies) and rare-to-occasional erythrocytic basophilic stippling were observed in the peripheral blood smears of female mice.^2,55^ Basophilic stippling represents ribosomal aggregates within the cytoplasm of erythrocytes and is associated with disruptions in erythropoiesis. In the current study, mild dysplasia of bone marrow metarubricytes (late-stage erythropoietic precursor cells) was observed at both 3 and 12 months and included multilobulated nuclei, micronuclei, and nuclear-to-cytoplasmic asynchrony. The abnormal morphological findings in both the peripheral blood and bone marrow smears paired with the CBC findings indicate a disruption of normal erythropoiesis. In addition, the white blood cell count and differential showed moderate decreases with increasing dose at 3 months; these decreases ameliorated by 12 months.

As previously mentioned, these combinations of hematological changes are consistent with a condition known as megaloblastic anemia, which, despite its name, is a condition that can affect all three hematopoietic cell lines. Causes of megaloblastic anemia include inherited (e.g., orotic aciduria, transcobalamin II deficiency) or drug-induced (e.g., pyrimidine antagonists, antivirals) disorders or either a dietary or functional deficiency in folate or cobalamin (vitamin B_12_).^171,172^ In a prior NTP 3-month mouse study, circulating levels of homocysteine and methyl-malonic acid (MMA) were increased in female mice exposed to 1,000 mg/kg/day BCE.^2^ Homocysteine and MMA are two biomarkers used for the diagnosis or confirmation of folate (homocysteine only) or cobalamin deficiencies (homocysteine and MMA).^171,173^ Taken in its entirety, the results from previous NTP mouse studies and the current study are consistent with a BCE-induced disruption in cobalamin metabolism (functional cobalamin deficiency); however, the exact mechanism by which BCE disrupts cobalamin metabolism is not known at this time.

Megaloblastic anemia and its characteristic hematological changes result from deranged DNA synthesis.^171^ Folate and cobalamin are both involved in several interrelated metabolic cycles related to DNA and RNA synthesis, including those required for purine and thymidylate synthesis, as well as for the synthesis of methionine from homocysteine (methionine cycle).^171,174^ Thus, with folate or cobalamin deficiency, DNA synthesis is ultimately impaired. Within hematopoietic tissues, this impairment results in increased death of immature erythroid cells leading to a decrease in the erythron or anemia.^175^ Surviving erythroid cells are delayed in their maturation, which leads to a larger cell size (macrocytosis) and is reflected in an increase in the MCV. In addition, and depending on the cause, severity, and species, megaloblastic anemia will manifest with decreases in white blood cells or platelets with or without dysplastic changes (e.g., giant metamyelocytes, hypersegmented neutrophils).

Increased frequencies of micronucleated peripheral blood erythrocytes were observed in female mice administered ≥100 mg/kg/day for 3 months. This finding is consistent with a previous 3-month NTP study, which showed a significant increase in micronucleated erythrocytes in female B6C3F1/N mice starting at doses of 250 mg/kg/day.^55^ Interestingly, the magnitude of the BCE effect in the micronucleus assay remained similar at the 12-month evaluation, suggesting no alteration in the genotoxicity response associated with increasing duration of BCE administration. A variety of genotoxicity studies has been conducted using the same lot of BCE as was used in this study, including bacterial mutation assays, in vitro chromosomal damage (micronucleus) assays, in vitro DNA damage (comet) assays, in vivo micronucleus assays in female rats and mice, and specialized in vitro assays that provide information on the mechanism of action. All but the bacterial mutation assays have shown significant effects.^55,114-116^ A significant increase in DNA damage as measured by the comet assay was observed by Seo et al.^116^; however, the DNA damage occurred at a high BCE concentration, was transient, and returned to near-baseline levels after 2 hours of exposure. Seo et al.^116^ concluded the results did not contradict the negative conclusions for clastogenic activity drawn from other tests.^114,115^ Further, Seo et al.^116^ concluded that black cohosh induces chromosomal alterations, manifested as micronuclei, via an aneugenic mechanism that involves microtubule destabilization during mitosis, as observed by Bernacki et al.^115^ Rodent carcinogens constitute a high proportion of the compounds that conclusively induce micronuclei in rodents.^163^ However, aneugens are not DNA-reactive and typically are assumed to have a threshold effect for carcinogenicity, such that below a certain level of exposure there is a low risk of tumor induction via a genotoxic mechanism of action.^176^ Since a positive carcinogenic effect was not observed at the doses used in the present NTP studies, this threshold might not have been reached. The destabilization of tubulin induced by BCE may play a role in the induction of megaloblastic anemia observed in this and other NTP studies^2,55^ with female rats and mice exposed to BCE. Another compound, colchicine, is also associated with development of megaloblastic anemia resulting from a functional cobalamin deficiency,^115,177^ and colchicine is a well-characterized aneugen. The role of tubulin in uptake and intracellular distribution of cobalamin has not yet been characterized.^115,178,179^ Taken together, the accumulated evidence to date points to an aneugenic, threshold mechanism of action for induction of micronuclei by BCE. Because the tubulin-destabilizing, genotoxic component of BCE has not yet been identified, it is difficult to evaluate the relevance of these genotoxic findings to humans as the internal concentrations of the active component cannot be compared.

No neoplasms were considered related to BCE administration in female mice. Nonneoplastic lesions related to BCE administration over 2 years were identified in the liver (necrosis) and thyroid gland (follicle dilation). These lesions were minimal to moderate in severity, and incidences were increased primarily in the highest dosed group (1,000 mg/kg/day). The incidence of liver necrosis (of minimal severity) was significantly increased in female mice in the highest dosed group. In previous 3-month gavage studies, mild liver necrosis was noted in female rats but not in female mice.^55^ The lack of changes in biomarkers or any microscopic changes related to the liver in previous studies in B6C3F1/N mice administered the same BCE doses for 3 months,^55^ combined with the minimal necrosis observed in these 2-year studies, suggest limited hepatotoxicity of BCE in rodents. Follicular dilation in the thyroid gland is a common age-related lesion observed in rodents^180^; however, given the connection of estrogen to thyroid gland function,^181^ the significant increase could be related to disrupted estrogen hormonal balance or signaling from BCE.