# Results

## Data Availability

All study data were evaluated. Data relevant for evaluating toxicological findings are presented here. All study data are available in the National Toxicology Program (NTP) Chemical Effects in Biological Systems (CEBS) database: https://doi.org/10.22427/NTP-DATA-TR-603.^164^

## Rats

### Two-year Study (Perinatal Phase)

No changes in dam survival, pregnancy status, number of dams littered, or gestation length were related to administration of black cohosh root extract (BCE) (Table 2).

Table 2 Summary of the Disposition of F_0_ Female Rats during Perinatal Exposure in the Perinatal and Two-year Gavage Study of Black Cohosh Root Extract

| 0 mg/kg/day | 75 mg/kg/day | 250 mg/kg/day | 750 mg/kg/day
Reproductive Performance
Time-mated Females (GD 6) | 38 | 38 | 38 | 38
Females Pregnant (%)^a^ | 33 (86.8) | 32 (84.2) | 34 (89.5) | 36 (94.7)
Females Not Pregnant (%) | 5 (13.2) | 6 (15.8) | 4 (10.5) | 2 (5.3)
Dams Not Delivering with Evidence of Pregnancy (%) | 2 (6.1) | 0 (0) | 2 (5.9) | 1 (2.8)
Dams with Litters on LD 0 (%)^a^ | 31 (93.9) | 32 (100.0) | 32 (94.1) | 35 (97.2)
Gestation Length (Days)^b,c^ | 22.3 ± 0.1 (31) | 22.2 ± 0.1 (32) | 22.2 ± 0.1 (32) | 22.3 ± 0.1 (35)
Litters Poststandardization (PND 4)^d^ | 30 | 30 | 30 | 30
Weaned Males/Females | 121/116 | 122/117 | 117/115 | 122/112

GD = gestation day; LD = lactation day; PND = postnatal day.

^a^ Statistical analysis performed by the Cochran-Armitage (trend) and Fisher’s exact (pairwise) tests. No statistically significant findings were noted at p ≤ 0.05.

^b^ Statistical analysis performed by the Jonckheere (trend) and Shirley or Dunn (pairwise) tests. No statistically significant findings were noted at p ≤ 0.05.

^c^ Gestation length calculated for sperm-positive females that delivered a litter. Data are presented as mean ± standard error (number of dams).

^d^ Standardization to eight pups/litter (four pups/sex).

Mean body weights of dams administered BCE were lower than that of vehicle control animals throughout gestation and lactation; changes in body weight were within 10% of vehicle control animals (Table 3). Beginning around gestation day (GD) 9, mean body weights of animals administered 250 or 750 mg BCE/kg body weight/day (mg/kg/day) were significantly decreased (up to 8% less in the 750 mg/kg/day group) compared to that of vehicle control animals. There was a negative trend in mean body weights with increasing dose at most time points during gestation and lactation. During lactation, the differences were consistently significant in the 750 mg/kg/day group from lactation day (LD) 1 through LD 25 and in the 250 mg/kg/day group from LD 1 through LD 14 (Table 3). Dam body weight changes were significantly decreased in all dosed groups compared to the vehicle control group for gestation interval GD 6–21 but tended to be higher than that in the vehicle control group for lactation interval LD 1–28.

Table 3 Summary of Mean Body Weights and Body Weight Gains of F_0_ Female Rats during Gestation and Lactation in the Perinatal and Two-year Gavage Study of Black Cohosh Root Extract

Parameter^a,b^ | 0 mg/kg/day | 75 mg/kg/day | 250 mg/kg/day | 750 mg/kg/day
Gestation Body Weight
Gestation Day
6 | 234.5 ± 1.5 (33) | 237.5 ± 2.2 (32) | 233.4 ± 2.4 (34) | 234.8 ± 2.3 (36)
9 | 253.9 ± 1.4** (33) | 248.8 ± 3.0 (32) | 244.1 ± 2.0** (34) | 241.2 ± 2.2** (36)
12 | 269.0 ± 1.4** (33) | 264.1 ± 2.0 (32) | 260.7 ± 2.1** (34) | 257.0 ± 2.3** (36)
15 | 286.7 ± 1.9** (33) | 281.0 ± 2.7 (32) | 276.4 ± 2.4** (34) | 271.6 ± 2.2** (36)
18 | 331.0 ± 2.8** (33) | 325.6 ± 2.9 (32) | 319.0 ± 3.7** (34) | 309.0 ± 2.6** (36)
21 | 378.0 ± 4.2** (33) | 365.9 ± 4.8 (32) | 363.1 ± 5.6* (34) | 347.4 ± 3.4** (36)
Gestation Weight Change
Gestation Day Interval
6–9 | 19.3 ± 1.2** (33) | 11.2 ± 1.1** (32) | 10.7 ± 1.5** (34) | 6.4 ± 1.1** (36)
9–12 | 15.2 ± 1.1 (33) | 15.3 ± 1.5 (32) | 16.6 ± 1.0 (34) | 15.8 ± 1.5 (36)
12–15 | 17.7 ± 1.2* (33) | 16.9 ± 1.0 (32) | 15.7 ± 1.0 (34) | 14.6 ± 1.5 (36)
15–18 | 44.3 ± 1.6** (33) | 44.6 ± 1.3 (32) | 42.6 ± 1.7 (34) | 37.4 ± 1.2** (36)
18–21 | 46.9 ± 1.7** (33) | 40.3 ± 3.1 (32) | 44.0 ± 2.2 (34) | 38.4 ± 1.9** (36)
6–21 | 143.4 ± 4.1** (33) | 128.4 ± 4.5* (32) | 129.7 ± 5.1* (34) | 112.6 ± 3.2** (36)
Lactation Body Weight
Lactation Day
1 | 279.6 ± 2.5** (31) | 274.0 ± 2.3 (32) | 271.8 ± 2.6* (32) | 266.9 ± 2.4** (35)
4 | 293.4 ± 2.1** (31) | 285.5 ± 2.6* (32) | 285.2 ± 2.7* (32) | 277.5 ± 2.2** (35)
7^c^ | 301.9 ± 2.5** (30) | 293.4 ± 2.3* (30) | 291.9 ± 3.1** (30) | 285.8 ± 2.1** (30)
14 | 321.9 ± 2.5** (30) | 312.7 ± 2.7* (30) | 313.1 ± 2.9* (29)^c^ | 308.6 ± 2.6** (30)
21 | 305.8 ± 2.8** (30) | 299.6 ± 3.0 (30) | 299.7 ± 2.5 (29) | 288.4 ± 2.7** (30)
25 | 295.1 ± 2.0 (30) | 289.8 ± 2.8 (30) | 292.5 ± 2.6 (29) | 285.2 ± 3.2* (30)
28 | 289.5 ± 2.5 (30) | 284.3 ± 3.2 (30) | 286.1 ± 2.8 (29) | 285.5 ± 2.2 (29)^c^
Lactation Weight Change
Lactation Day Interval
1–4 | 13.7 ± 1.9 (31) | 11.5 ± 1.3 (32) | 13.3 ± 1.7 (32) | 10.7 ± 1.4 (35)
4–7^c^ | 8.0 ± 1.9 (30) | 6.2 ± 1.6 (30) | 7.2 ± 2.8 (30) | 9.6 ± 1.3 (30)
7–10 | 8.7 ± 1.9 (30) | 10.6 ± 1.7 (30) | 8.9 ± 1.8 (29)^c^ | 12.7 ± 1.2 (30)
10–14 | 11.3 ± 1.8 (30) | 8.6 ± 2.3 (30) | 11.5 ± 1.1 (29) | 10.1 ± 1.7 (30)
14–18 | −9.7 ± 1.7 (30) | −6.7 ± 1.8 (30) | −4.6 ± 1.2 (29) | −6.1 ± 1.7 (30)
18–21 | −6.3 ± 2.0** (30) | −6.3 ± 1.9 (30) | −8.8 ± 2.2 (29) | −14.1 ± 1.8** (30)
21–25 | −10.7 ± 2.2** (30) | −9.9 ± 1.3 (30) | −7.2 ± 1.8 (29) | −3.3 ± 3.5* (30)
25–28 | −5.5 ± 1.4 (30) | −5.4 ± 1.3 (30) | −6.4 ± 0.9 (29) | 0.4 ± 2.8* (29)^c^
1–28 | 9.9 ± 2.5** (30) | 8.9 ± 2.9 (30) | 14.9 ± 2.1 (29) | 20.9 ± 2.2** (29)

Statistical significance for a dosed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ Data are presented as mean ± standard error (number of dams). Body weight data are presented in grams.

^b^ Each dosed group was compared to the vehicle control group with the Williams test when a trend was present (p ≤ 0.01 from the Jonckheere trend test) or with the Dunnett test when no trend was present.

^c^ Changes in n are the result of standardization on lactation day (LD) 4 and removing litters with no surviving pups by LD 8 (one litter in the 250 mg/kg/day group) and LD 28 (one litter in the 750 mg/kg/day group).

Total and live litter sizes were significantly decreased in the 750 mg/kg/day group relative to the vehicle control group on postnatal day (PND) 1 and PND 4 (combined male and female prestandardization) only (Table 4).

Table 4 Summary of Mean Litter Size and Survival Ratio of F_1_ Male and Female Rats during Lactation in the Perinatal and Two-year Gavage Study of Black Cohosh Root Extract

Parameter | 0 mg/kg/day | 75 mg/kg/day | 250 mg/kg/day | 750 mg/kg/day
PND 1
Total^a,b^ | 13.10 ± 0.45* (31) | 12.52 ± 0.61 (31) | 13.09 ± 0.41 (32) | 11.69 ± 0.47* (35)
Live^b^ | 13.23 ± 0.40** (30) | 12.45 ± 0.60 (31) | 12.97 ± 0.42 (32) | 11.51 ± 0.46** (35)
% Male/Litter^a,b,c^ | 50.5 ± 2.1 (28) | 49.4 ± 3.5 (23) | 50.0 ± 2.8 (24) | 52.8 ± 3.0 (34)
% Male^c,d,e^ | 50.1 (369) | 51.8 (280) | 50.5 (307) | 52.4 (389)
Male^a,b^
PND 1^c^ | 6.61 ± 0.30 (28) | 6.30 ± 0.54 (23) | 6.46 ± 0.47 (24) | 6.00 ± 0.40 (34)
PND 4 Prestandardization^c^ | 6.61 ± 0.30 (28) | 6.26 ± 0.53 (23) | 6.38 ± 0.47 (24) | 6.09 ± 0.40 (33)
PND 4 Poststandardization | 4.07 ± 0.07 (30) | 4.10 ± 0.10 (30) | 4.03 ± 0.06 (30) | 4.17 ± 0.14 (30)
Female^a,b^
PND 1^c^ | 6.57 ± 0.38 (28) | 5.87 ± 0.49 (23) | 6.33 ± 0.42 (24) | 5.44 ± 0.37 (34)
PND 4 Prestandardization^c^ | 6.57 ± 0.38 (28) | 5.83 ± 0.51 (23) | 6.29 ± 0.42 (24) | 5.52 ± 0.35 (33)
PND 4 Poststandardization | 3.93 ± 0.07 (30) | 3.90 ± 0.10 (30) | 3.97 ± 0.06 (30) | 3.83 ± 0.14 (30)
Male and Female^a,b^
PND 4 Prestandardization | 13.23 ± 0.40** (30) | 12.39 ± 0.60 (31) | 12.84 ± 0.42 (32) | 11.34 ± 0.51** (35)
PND 4 Poststandardization | 8.00 ± 0.00 (30) | 8.00 ± 0.00 (30) | 8.00 ± 0.00 (30) | 8.00 ± 0.00 (30)
PND 28 | 7.90 ± 0.06 (30) | 7.93 ± 0.05 (30) | 7.73 ± 0.27 (30) | 7.53 ± 0.27 (30)
Survival per Litter
Total Dead: PND 1–4^e,f^ | 9 (3) | 4 (4) | 8 (7) | 12 (9)
Total Dead: PND 4–28^e,f^ | 3 (3) | 2 (2) | 8 (1) | 14 (6)
Dead/Litter: PND 1–4^a,b^ | 0.29 ± 0.18 (31) | 0.13 ± 0.06 (31) | 0.25 ± 0.09 (32) | 0.34 ± 0.12 (35)
Dead/Litter: PND 4–28^a,b^ | 0.10 ± 0.06 (30) | 0.07 ± 0.05 (30) | 0.27 ± 0.27 (30) | 0.47 ± 0.27 (30)
Survival Ratio: PND 1–4^a,b,g^ | 1.000 ± 0.000 (30) | 0.995 ± 0.004 (31) | 0.991 ± 0.006 (32) | 0.965 ± 0.029 (35)
Survival Ratio: PND 4–28^a,b,h^ | 0.988 ± 0.007 (30) | 0.992 ± 0.006 (30) | 0.967 ± 0.033 (30) | 0.942 ± 0.034 (30)

Statistical significance for a dosed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

PND = postnatal day.

^a^ Each dosed group was compared to the vehicle control group with the Shirley test when a trend was present (p ≤ 0.01 from the Jonckheere trend test) or with the Dunn test when no trend was present.

^b^ Data are presented as mean ± standard error (number of litters).

^c^ Litters in which the male/female pup counts were inconsistent between PND 1 and PND 4 were excluded from the male/female-specific endpoints.

^d^ [100 × (number of live males in dosed group)/(number of live males and females in dosed group)](number of pups).

^e^ No statistical analysis performed on this endpoint.

^f^ Total number of dead pups in dosed group (number of litters contributing dead pups).

^g^ Survival/litter: Number of pups prestandardization on PND 4/number of live pups on PND 1.

^h^ Survival/litter: Number of live pups on PND 28/number of live pups poststandardization on PND 4.

There was a marginal decrease in pup survival ratio from PND 1 to PND 4, but no significant differences in pup survival were observed during lactation (Table 4). Mean body weights of BCE-exposed pups were within 12% of the vehicle control groups (Table 5). Pups tended to gain less weight with increasing exposure, resulting in significantly different mean body weights relative to the vehicle control pups at all time points from PND 1 until weaning on PND 28. Male and female pup mean body weights of the 750 mg/kg/day groups were significantly different from those of the vehicle control groups throughout the lactation period; the difference ranged from 8% to 11% (male pups) or from 10% to 12% (female pups). In the 250 mg/kg/day group, female pups had significantly different mean body weights (5%–8% less than that of the vehicle control group) starting from PND 12 until weaning; this was not observed in male pups.

Table 5 Summary of Preweaning F_1_ Male and Female Rat Pup Mean Body Weights Following Perinatal Exposure to Black Cohosh Root Extract

Parameter | 0 mg/kg/day | 75 mg/kg/day | 250 mg/kg/day | 750 mg/kg/day
Male (g)
PND 1^a,b,c,d^ | 7.08 ± 0.10** (28) | 6.85 ± 0.11 (22) | 6.94 ± 0.17 (24) | 6.64 ± 0.12* (34)
PND 4^e,f,g,h^ | 10.24 ± 0.17** (197/30) | 9.88 ± 0.18 (206/30) | 9.96 ± 0.17 (210/32) | 9.17 ± 0.17** (208/34)
PND 7^e,f,i^ | 15.36 ± 0.35* (122/30) | 14.90 ± 0.38 (123/30) | 14.84 ± 0.44 (121/30) | 14.03 ± 0.34* (124/30)
PND 12^e,f,i^ | 26.80 ± 0.45** (121/30) | 26.14 ± 0.50 (123/30) | 25.63 ± 0.58 (117/29) | 24.14 ± 0.54** (122/30)
PND 15^e,f,i^ | 34.20 ± 0.50** (121/30) | 33.47 ± 0.58 (122/30) | 32.64 ± 0.60 (117/29) | 31.44 ± 0.65** (122/30)
PND 18^e,f,i^ | 41.51 ± 0.70** (121/30) | 40.71 ± 0.69 (122/30) | 40.01 ± 0.74 (117/29) | 38.00 ± 0.78** (122/30)
PND 21^e,f,i^ | 53.66 ± 0.81** (121/30) | 52.41 ± 0.89 (122/30) | 50.67 ± 1.06 (117/29) | 47.96 ± 1.00** (122/30)
PND 24^e,f,i^ | 67.94 ± 1.09** (121/30) | 66.24 ± 1.10 (122/30) | 63.88 ± 1.31* (117/29) | 60.30 ± 1.24** (122/30)
PND 28^e,f,i^ | 88.35 ± 1.31** (121/30) | 86.75 ± 1.24 (122/30) | 83.85 ± 1.60 (117/29) | 79.26 ± 1.56** (122/30)
Female (g)
PND 1^a,b,c,d^ | 6.79 ± 0.11* (28) | 6.51 ± 0.08 (23) | 6.59 ± 0.16 (24) | 6.38 ± 0.12* (33)
PND 4^e,f,g,h^ | 9.75 ± 0.18** (200/30) | 9.28 ± 0.18 (177/31) | 9.29 ± 0.16 (201/32) | 8.70 ± 0.17** (189/34)
PND 7^e,f,i^ | 14.75 ± 0.38** (118/30) | 13.91 ± 0.35 (117/30) | 13.73 ± 0.41 (119/30) | 13.18 ± 0.34** (115/30)
PND 12^e,f,i^ | 26.00 ± 0.53** (117/30) | 24.52 ± 0.52 (117/30) | 24.14 ± 0.55* (115/29) | 22.89 ± 0.53** (112/30)
PND 15^e,f,i^ | 33.24 ± 0.57** (117/30) | 31.31 ± 0.57 (117/30) | 30.91 ± 0.58* (115/29) | 29.96 ± 0.65** (112/30)
PND 18^e,f,i^ | 40.39 ± 0.76** (117/30) | 38.11 ± 0.68 (117/30) | 37.83 ± 0.73* (115/29) | 36.45 ± 0.76** (112/30)
PND 21^e,f,i^ | 51.29 ± 0.85** (117/30) | 48.43 ± 0.85 (117/30) | 47.29 ± 0.92** (115/29) | 45.40 ± 0.99** (112/30)
PND 24^e,f,i^ | 63.70 ± 1.13** (117/30) | 60.34 ± 1.01 (117/30) | 59.03 ± 1.14* (115/29) | 56.64 ± 1.18** (112/30)
PND 28^e,f,i^ | 80.26 ± 1.17** (116/30) | 77.06 ± 1.09 (117/30) | 75.21 ± 1.34* (115/29) | 72.22 ± 1.39** (112/30)
Male and Female (g)
PND 1^a,b,c^ | 6.95 ± 0.10** (30) | 6.65 ± 0.07 (31) | 6.68 ± 0.12 (32) | 6.48 ± 0.11** (35)
PND 4^e,f,g,h^ | 10.00 ± 0.17** (397/30) | 9.57 ± 0.18 (383/31) | 9.64 ± 0.16 (411/32) | 8.94 ± 0.16** (397/34)
PND 7^e,f,i^ | 15.05 ± 0.35** (240/30) | 14.42 ± 0.36 (240/30) | 14.29 ± 0.41 (240/30) | 13.64 ± 0.31* (239/30)
PND 12^e,f,i^ | 26.41 ± 0.47** (238/30) | 25.37 ± 0.50 (240/30) | 24.90 ± 0.55 (232/29) | 23.57 ± 0.50** (234/30)
PND 15^e,f,i^ | 33.73 ± 0.50** (238/30) | 32.42 ± 0.56 (239/30) | 31.79 ± 0.57* (232/29) | 30.76 ± 0.61** (234/30)
PND 18^e,f,i^ | 40.96 ± 0.70** (238/30) | 39.45 ± 0.67 (239/30) | 38.93 ± 0.71 (232/29) | 37.25 ± 0.74** (234/30)
PND 21^e,f,i^ | 52.49 ± 0.79** (238/30) | 50.46 ± 0.86 (239/30) | 49.01 ± 0.97* (232/29) | 46.79 ± 0.94** (234/30)
PND 24^e,f,i^ | 65.86 ± 1.07** (238/30) | 63.34 ± 1.03 (239/30) | 61.49 ± 1.19* (232/29) | 58.58 ± 1.14** (234/30)
PND 28^e,f,i^ | 84.41 ± 1.19** (237/30) | 82.00 ± 1.13 (239/30) | 79.58 ± 1.43* (232/29) | 75.94 ± 1.38** (234/30)

Statistical significance for a dosed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

PND = postnatal day.

^a^ Data are presented as mean ± standard error (number of litters).

^b^ Each dosed group was compared to the vehicle control group with the Williams test when a trend was present (p ≤ 0.01 from the Jonckheere trend test) or with the Dunnett test when no trend was present.

^c^ Total litter weight at PND 1 divided by number of live pups in litter at PND 1.

^d^ Litters in which the male/female pup counts were inconsistent between PND 1 and PND 4 were excluded from the male/female-specific endpoints.

^e^ Statistical analysis performed using linear mixed models with random litter effect for both trend and pairwise tests, using the Dunnett-Hsu adjustment for multiple comparisons.

^f^ Data are presented as the mean of litter means ± standard error (number of pups/number of litters).

^g^ PND 4 prestandardization.

^h^ Individual pup weights first adjusted for live litter size on PND 1. Litters with differing pup counts between PND 1 and PND 4 were excluded.

^i^ Individual pup weights first adjusted for live litter size on PND 4 poststandardization.

### Two-year Study (Postweaning Phase)

After weaning, female rats were administered BCE via daily gavage at the same dose as their respective dams. Male rats were not administered BCE or the vehicle during the postweaning phase. Consequently, “exposed male rats” hereafter refers to animals that experienced perinatal BCE exposure only; “exposure concentration of male rats” refers to the dose their respective dams received.

Estimates of 2-year survival probabilities for male and female rats are shown in Table 6 and in the Kaplan-Meier survival curves (Figure 2). Survival of all groups of exposed male rats was not significantly different from the vehicle control group. There was a slightly lower survival rate (p = 0.055) of female rats in the 750 mg/kg/day group.

Table 6 Summary of Survival of Male and Female Rats in the Perinatal and Two-year Gavage Study of Black Cohosh Root Extract

| 0 mg/kg/day | 75 mg/kg/day | 250 mg/kg/day | 750 mg/kg/day
Male
Animals Initially in Study | 50 | 50 | 50 | 50
Moribund | 16 | 14 | 11 | 8
Natural Deaths | 19 | 21 | 18 | 26
Animals Surviving to Study Termination | 15 | 15 | 21 | 16
Percent Probability of Survival at Study Termination^a^ | 30.0 | 30.0 | 42.0 | 32.0
Mean Survival (Days)^b^ | 655.8 ± 15.3 | 647.3 ± 18.0 | 658.5 ± 15.4 | 650.7 ± 13.7
Survival Analysis^c^ | p = 0.903 | p = 0.541 | p = 0.596N | p = 0.747
Female
Animals Initially in Study | 50 | 50 | 50 | 50
Moribund | 13 | 14 | 15 | 14
Natural Deaths | 9 | 12 | 6 | 16
Animals Surviving to Study Termination | 28 | 24 | 29 | 20
Percent Probability of Survival at Study Termination | 56.0 | 48.0 | 58.0 | 40.0
Mean Survival (Days) | 679.2 ± 9.3 | 655.6 ± 15.4 | 684.7 ± 12.5 | 632.3 ± 15.9
Survival Analysis | p = 0.056 | p = 0.398 | p = 0.784N | p = 0.055

^a^ Kaplan-Meier determinations.

^b^ Mean of litter means of all deaths (uncensored, censored, and study termination) ± standard error.

^c^ The result of the Cox proportional hazards trend test is in the vehicle control group column, and the results of the Cox proportional hazards pairwise comparisons to the vehicle control group are in the dosed group columns. A negative trend or lower mortality in a dosed group is indicated by N.

Figure 2

Kaplan-Meier Survival Curves for Male Rats Exposed Perinatally and Female Rats Exposed Perinatally and Administered Black Cohosh Root Extract by Gavage for Two Years

Survival curves are shown for (A) males and (B) females.

Throughout the study, groups of BCE-exposed male rats had mean body weights within 12% of that of the vehicle control males (Table 7; Figure 3). Mean body weights of the female 75 and 250 mg/kg/day groups were within 10% of that of the vehicle control group throughout the study (Table 8; Figure 3). The mean body weight of the 750 mg/kg/day female group was generally within 10% of that of the vehicle control group until study day 309 and thereafter ranged from 12% to 18% less than that of the vehicle control group until study termination.

Table 7 Summary of Survival and Mean Body Weights of Male Rats Exposed Perinatally in the Perinatal and Two-year Study of Black Cohosh Root Extract

Study Day^a^ | 0 mg/kg/day | | 75 mg/kg/day | | | 250 mg/kg/day | | | 750 mg/kg/day
Study Day^a^ | Av. Wt. (g)^b^ | No. of Litters | Av. Wt. (g) | Wt. (% of Controls) | No. of Litters | Av. Wt. (g) | Wt. (% of Controls) | No. of Litters | Av. Wt. (g) | Wt. (% of Controls) | No. of Litters
1 | 97.4 | 25 | 97.7 | 100.3 | 25 | 93.8 | 96.3 | 25 | 88.5 | 90.8 | 25
8 | 141.0 | 25 | 141.9 | 100.7 | 25 | 137.5 | 97.5 | 25 | 126.1 | 89.4 | 25
15 | 192.4 | 25 | 192.3 | 100.0 | 25 | 184.5 | 95.9 | 25 | 178.8 | 93.0 | 25
22 | 243.6 | 25 | 243.2 | 99.8 | 25 | 235.2 | 96.5 | 25 | 226.8 | 93.1 | 25
29 | 288.2 | 25 | 287.6 | 99.8 | 25 | 277.9 | 96.4 | 25 | 267.5 | 92.8 | 25
36 | 320.7 | 25 | 311.9 | 97.3 | 25 | 309.3 | 96.5 | 25 | 292.0 | 91.0 | 25
43 | 347.2 | 25 | 345.5 | 99.5 | 25 | 337.1 | 97.1 | 25 | 318.0 | 91.6 | 25
50 | 365.7 | 25 | 366.5 | 100.2 | 25 | 357.2 | 97.7 | 25 | 335.5 | 91.7 | 25
57 | 377.7 | 25 | 385.4 | 102.0 | 25 | 372.5 | 98.6 | 25 | 353.1 | 93.5 | 25
64 | 394.9 | 25 | 397.6 | 100.7 | 25 | 387.5 | 98.1 | 25 | 367.1 | 93.0 | 25
71 | 406.6 | 25 | 409.8 | 100.8 | 25 | 397.7 | 97.8 | 25 | 376.5 | 92.6 | 25
78 | 417.8 | 25 | 418.2 | 100.1 | 25 | 404.0 | 96.7 | 25 | 385.9 | 92.4 | 25
85 | 428.8 | 25 | 426.8 | 99.5 | 25 | 413.3 | 96.4 | 25 | 394.3 | 92.0 | 25
113 | 460.7 | 25 | 459.1 | 99.6 | 25 | 446.4 | 96.9 | 25 | 423.3 | 91.9 | 25
141 | 478.8 | 25 | 483.4 | 101.0 | 25 | 471.2 | 98.4 | 25 | 445.0 | 92.9 | 25
169 | 498.0 | 25 | 505.1 | 101.4 | 25 | 486.4 | 97.7 | 25 | 462.4 | 92.8 | 25
197 | 511.2 | 25 | 517.5 | 101.2 | 25 | 501.8 | 98.1 | 25 | 483.9 | 94.7 | 25
225 | 535.2 | 25 | 534.0 | 99.8 | 25 | 519.1 | 97.0 | 25 | 499.1 | 93.3 | 25
253 | 551.6 | 25 | 558.1 | 101.2 | 25 | 541.5 | 98.2 | 25 | 513.1 | 93.0 | 25
281 | 560.6 | 25 | 573.9 | 102.4 | 25 | 552.4 | 98.5 | 25 | 529.7 | 94.5 | 25
309 | 580.2 | 25 | 586.9 | 101.2 | 25 | 564.4 | 97.3 | 25 | 539.5 | 93.0 | 25
337 | 592.5 | 25 | 597.5 | 100.8 | 25 | 579.6 | 97.8 | 25 | 549.4 | 92.7 | 25
365 | 603.1 | 25 | 611.1 | 101.3 | 25 | 590.2 | 97.9 | 25 | 563.7 | 93.5 | 25
393 | 612.3 | 25 | 618.9 | 101.1 | 25 | 598.2 | 97.7 | 25 | 565.4 | 92.3 | 25
421 | 624.6 | 25 | 622.9 | 99.7 | 25 | 604.6 | 96.8 | 25 | 572.6 | 91.7 | 25
449 | 630.7 | 25 | 624.8 | 99.1 | 24 | 621.5 | 98.5 | 24 | 585.1 | 92.8 | 25
477 | 628.2 | 25 | 624.1 | 99.4 | 24 | 621.0 | 98.9 | 24 | 589.1 | 93.8 | 25
505 | 621.1 | 25 | 613.3 | 98.7 | 24 | 613.3 | 98.7 | 24 | 582.5 | 93.8 | 25
533 | 622.3 | 25 | 614.5 | 98.7 | 24 | 619.7 | 99.6 | 24 | 581.4 | 93.4 | 24
561 | 630.8 | 25 | 626.9 | 99.4 | 22 | 622.2 | 98.6 | 24 | 578.6 | 91.7 | 24
589 | 627.2 | 24 | 613.7 | 97.8 | 22 | 620.8 | 99.0 | 24 | 589.8 | 94.0 | 23
617 | 621.8 | 24 | 604.2 | 97.2 | 21 | 618.6 | 99.5 | 22 | 586.4 | 94.3 | 23
645 | 622.4 | 23 | 610.1 | 98.0 | 18 | 617.4 | 99.2 | 21 | 570.5 | 91.7 | 21
673 | 594.2 | 20 | 595.2 | 100.2 | 16 | 603.7 | 101.6 | 21 | 561.0 | 94.4 | 17
701 | 607.9 | 18 | 600.4 | 98.8 | 15 | 613.2 | 100.9 | 17 | 563.3 | 92.7 | 15
EOS | 628.4 | 13 | 566.7 | 90.2 | 11 | 606.8 | 96.6 | 16 | 557.3 | 88.7 | 11

No trend or pairwise statistical tests were performed on these data.

No. of litters = number of litters represented in weight average; EOS = end of study.

^a^ Study day 1 is the day animals were placed on study after pups were weaned.

^b^ Average weights shown are means of litter means.

Figure 3

Growth Curves for Male Rats Exposed Perinatally and Female Rats in the Perinatal and Two-year Gavage Study of Black Cohosh Root Extract

Growth curves are shown for (A) males and (B) females.

Table 8 Summary of Survival and Mean Body Weights of Female Rats in the Perinatal and Two-year Gavage Study of Black Cohosh Root Extract

StudyDay^a^ | 0 mg/kg/day | | 75 mg/kg/day | | | 250 mg/kg/day | | | 750 mg/kg/day
StudyDay^a^ | Av. Wt. (g)^b^ | No. of Litters | Av. Wt. (g) | Wt. (% of Controls) | No. of Litters | Av. Wt. (g) | Wt. (% of Controls) | No. of Litters | Av. Wt. (g) | Wt. (% of Controls) | No. of Litters
1 | 85.1 | 25 | 80.8 | 95.0 | 25 | 78.6 | 92.4 | 25 | 74.7 | 87.9 | 25
8 | 115.6 | 25 | 109.6 | 94.8 | 25 | 106.8 | 92.4 | 25 | 99.9 | 86.4 | 25
15 | 146.4 | 25 | 142.3 | 97.2 | 25 | 140.1 | 95.7 | 25 | 134.8 | 92.1 | 25
22 | 171.8 | 25 | 169.9 | 98.9 | 25 | 169.1 | 98.4 | 25 | 163.2 | 95.0 | 25
29 | 193.3 | 25 | 190.6 | 98.6 | 25 | 189.8 | 98.2 | 25 | 184.2 | 95.3 | 25
36 | 210.0 | 25 | 205.1 | 97.7 | 25 | 204.6 | 97.4 | 25 | 196.5 | 93.6 | 25
43 | 225.5 | 25 | 221.0 | 98.0 | 25 | 219.5 | 97.3 | 25 | 212.5 | 94.2 | 25
50 | 237.6 | 25 | 230.7 | 97.1 | 25 | 230.5 | 97.0 | 25 | 222.5 | 93.7 | 25
57 | 241.8 | 25 | 238.4 | 98.6 | 25 | 239.9 | 99.2 | 25 | 230.2 | 95.2 | 25
64 | 255.1 | 25 | 248.9 | 97.6 | 25 | 249.9 | 97.9 | 25 | 234.5 | 91.9 | 25
71 | 259.5 | 25 | 253.7 | 97.8 | 25 | 254.4 | 98.0 | 25 | 238.6 | 92.0 | 25
78 | 264.4 | 25 | 257.2 | 97.3 | 25 | 257.5 | 97.4 | 25 | 249.8 | 94.5 | 25
85 | 266.6 | 25 | 262.1 | 98.3 | 25 | 262.5 | 98.5 | 25 | 255.2 | 95.7 | 25
113 | 279.8 | 25 | 275.7 | 98.6 | 25 | 277.2 | 99.1 | 25 | 265.3 | 94.8 | 25
141 | 292.8 | 25 | 288.5 | 98.5 | 25 | 286.3 | 97.8 | 25 | 275.7 | 94.2 | 25
169 | 298.9 | 25 | 293.0 | 98.0 | 25 | 289.9 | 97.0 | 25 | 276.1 | 92.4 | 25
197 | 304.9 | 25 | 302.8 | 99.3 | 25 | 302.9 | 99.4 | 25 | 288.1 | 94.5 | 25
225 | 315.1 | 25 | 311.5 | 98.9 | 25 | 309.6 | 98.3 | 25 | 292.3 | 92.8 | 25
253 | 324.7 | 25 | 319.1 | 98.3 | 25 | 317.0 | 97.6 | 25 | 297.0 | 91.4 | 25
281 | 331.4 | 25 | 331.1 | 99.9 | 25 | 322.9 | 97.4 | 25 | 298.3 | 90.0 | 25
309 | 339.1 | 25 | 332.1 | 97.9 | 25 | 331.7 | 97.8 | 25 | 301.0 | 88.8 | 25
337 | 346.8 | 25 | 336.7 | 97.1 | 25 | 327.3 | 94.4 | 25 | 305.0 | 88.0 | 25
365 | 354.4 | 25 | 345.9 | 97.6 | 25 | 336.1 | 94.8 | 25 | 307.4 | 86.7 | 25
393 | 362.7 | 25 | 353.6 | 97.5 | 25 | 349.3 | 96.3 | 25 | 314.9 | 86.8 | 25
421 | 369.9 | 25 | 361.2 | 97.6 | 25 | 359.6 | 97.2 | 25 | 319.9 | 86.5 | 25
449 | 383.8 | 25 | 372.3 | 97.0 | 25 | 370.3 | 96.5 | 25 | 322.8 | 84.1 | 25
477 | 389.8 | 25 | 379.4 | 97.3 | 25 | 376.4 | 96.6 | 25 | 323.7 | 83.0 | 25
505 | 391.2 | 25 | 377.0 | 96.4 | 25 | 365.5 | 93.4 | 24 | 327.4 | 83.7 | 25
533 | 388.6 | 25 | 388.8 | 100.0 | 25 | 377.4 | 97.1 | 24 | 333.0 | 85.7 | 25
561 | 398.7 | 25 | 398.1 | 99.8 | 25 | 386.4 | 96.9 | 24 | 344.0 | 86.3 | 25
589 | 417.1 | 25 | 409.3 | 98.1 | 25 | 394.9 | 94.7 | 24 | 344.5 | 82.6 | 23
617 | 419.5 | 25 | 414.4 | 98.8 | 22 | 405.4 | 96.7 | 24 | 357.2 | 85.2 | 23
645 | 416.4 | 25 | 414.0 | 99.4 | 21 | 405.3 | 97.3 | 24 | 351.0 | 84.3 | 21
673 | 417.7 | 23 | 426.8 | 102.2 | 20 | 401.8 | 96.2 | 24 | 357.4 | 85.6 | 19
701 | 426.8 | 23 | 420.0 | 98.4 | 20 | 403.5 | 94.5 | 24 | 352.8 | 82.6 | 18
EOS | 417.1 | 22 | 418.7 | 100.4 | 19 | 388.8 | 93.2 | 22 | 361.6 | 86.7 | 16

No trend or pairwise statistical tests were performed on these data.

No. of litters = number of litters represented in weight average; EOS = end of study.

^a^ Study day 1 is the day animals were placed on study after pups were weaned.

^b^ Average weights shown are means of litter means.

No clinical observations in groups of exposed male or dosed female rats were considered related to BCE (Appendix E).

#### Histopathology

This section describes the statistically significant or biologically noteworthy changes in the incidence of neoplasms and nonneoplastic lesions of the uterus and ovary.

Uterus: Squamous cell papillomas and squamous cell carcinomas of the uterus were present in higher numbers in the 250 mg/kg/day group than in the vehicle control group, but there was not a significant difference between the incidences (Table 9). Squamous cell papillomas were characterized by well-circumscribed masses composed of papillary fronds of squamous epithelium with abundant overlying keratin. Squamous cell papillomas projected into the uterine lumen (Figure 4) and did not invade the underlying myometrium. In contrast, squamous cell carcinomas were poorly demarcated neoplasms arising from the endometrium, which invaded the underlying myometrium and often filled the uterine lumen with keratin. They were composed of variably differentiated squamous epithelial cells in nests and clusters that occasionally contained central keratin pearls. Neoplastic cells were typically polygonal, with abundant eosinophilic cytoplasm and round nuclei; intercellular bridges were visible between some of the cells.

Table 9 Incidences of Neoplastic and Nonneoplastic Lesions of the Uterus in Female Rats in the Perinatal and Two-year Gavage Study of Black Cohosh Root Extract

| 0 mg/kg/day | 75 mg/kg/day | 250 mg/kg/day | 750 mg/kg/day
n ^a^ | 50 | 50 | 50 | 49
Squamous Metaplasia^b^ | 21** (1.8)^c^ | 25 (1.4) | 30 (2.1) | 38** (2.3)
Dilation | 2** (4.0) | 3 (3.3) | 9* (3.4) | 22** (3.8)
Hemorrhage | 1** (3.0) | 0 | 0 | 8* (3.1)
Thrombus | 1* | 0 | 5 | 5
Ulcers | 0** | 1 (1.0) | 3 (1.7) | 9** (2.7)
Squamous Cell Papilloma^d^
Overall rate^e^ | 1/50 (2%) | 1/50 (2%) | 4/50 (8%) | 0/49 (0%)
Rate/litters^f^ | 1/25 (4%) | 1/25 (4%) | 4/25 (16%) | 0/25 (0%)
Adjusted rate^g^ | 2.4% | 2.5% | 9.2% | 0%
Rao-Scott-adjusted Poly-3 test^h^ | p = 0.397N | p = 0.733 | p = 0.232 | p = 0.527N
Squamous Cell Carcinoma^i^ | 1 | 0 | 2 | 1
Squamous Cell Papilloma or Squamous Cell Carcinoma (Combined)^j^
Overall rate | 2/50 (4%) | 1/50 (2%) | 4/50 (8%) | 1/49 (2%)
Rate/litters | 2/25 (8%) | 1/25 (4%) | 4/25 (16%) | 1/25 (4%)
Adjusted rate | 4.8% | 2.5% | 9.2% | 2.9%
Rao-Scott-adjusted Poly-3 test | p = 0.511N | p = 0.507N | p = 0.363 | p = 0.534N

Statistical significance for a dosed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant (p ≤ 0.05) from the vehicle control group by the Rao-Scott-adjusted Poly-3 test; **p ≤ 0.01.

^a^ Number of animals with tissue examined microscopically.

^b^ Number of animals with lesion.

^c^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

^d^ Historical control incidence for 2-year methylcellulose gavage study of trans-resveratrol: 0/50; all routes (mean ± standard deviation): 1/500 (0.2% ± 0.63%); range: 0% to 2%.

^e^ Number of animals with neoplasm/number of animals necropsied.

^f^ Number of litters with neoplasm-bearing animals/number of litters examined at site.

^g^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^h^ Beneath the control incidence is the p value associated with the trend test. Beneath the dosed group incidence is the p value corresponding to pairwise comparisons between the vehicle control group and that dosed group. The Rao-Scott test adjusts the Poly-3 test (which accounts for differential mortality in animals that do not reach study termination) for within-litter correlation. A negative trend or a lower incidence in a dosed group is indicated by N.

^i^ Historical control incidence for 2-year methylcellulose gavage study of trans-resveratrol: 0/50; all routes: 4/500 (0.8% ± 1.4%); range: 0% to 4%.

^j^ Historical control incidence for 2-year methylcellulose gavage study of trans-resveratrol: 0/50; all routes: 5/500 (1% ± 1.7%); range: 0% to 4%.

Figure 4

Representative Image of a Squamous Cell Papilloma in the Uterus of a Female Rat in the Perinatal and Two-year Gavage Study of Black Cohosh Root Extract (H&E)

A squamous cell papilloma (arrow) is present within the lumen of the uterus of a 250 mg/kg/day rat (2.6×). Because of sectioning, the stalk attaching the papilloma to the wall of the uterine lumen is not present in this section. Squamous metaplasia is also present. H&E = hematoxylin and eosin stain.

Nonneoplastic lesions observed in the uterus included squamous metaplasia, dilation, hemorrhage, thrombus, and ulcers. There was a positive trend for the incidence of squamous metaplasia, and the incidence was significantly increased in the 750 mg/kg/day group compared to the vehicle control group (Table 9). Squamous metaplasia involved either the endometrial glands, the luminal epithelium, or both, and was characterized by a replacement of the normal epithelium with squamous epithelium (Figure 5).

Figure 5

Representative Images of a Normal Uterus and Squamous Metaplasia of the Uterus in Female Rats in the Perinatal and Two-year Gavage Study of Black Cohosh Root Extract (H&E)

(A) Normal lining of the uterus from a vehicle control rat is shown (8×). The luminal epithelium is low cuboidal to columnar (arrows). (B) Squamous metaplasia of the luminal epithelium in the uterus of a 250 mg/kg/day female rat is shown (8×). The lining of the endometrium is replaced by squamous epithelium (arrows) instead of the regular cuboidal or columnar epithelium. An associated orthokeratotic hyperkeratosis (asterisks) is shown, which is commonly seen with squamous metaplasia of the epithelium. (C) Squamous metaplasia of endometrial glands in the uterus of a 250 mg/kg/day female rat is shown (8×). Squamous metaplasia can also involve the glands in the endometrium (arrows). H&E = hematoxylin and eosin stain.

Significantly increased incidences of uterine dilation occurred in the 250 and 750 mg/kg/day groups compared to the vehicle control group (Table 9). Most of the occurrences of dilation were marked in severity, causing thinning of the uterine wall (Figure 6) and loss of endometrial glands. The remaining uterine parenchyma frequently contained mixed inflammatory cells, hemorrhage, necrotic cell debris, and fibrin.

Figure 6

Representative Image of Dilation of the Uterus of a Female Rat in the Perinatal and Two-year Gavage Study of Black Cohosh Root Extract (H&E)

Dilation of the uterus from a 750 mg/kg/day rat is shown (0.5×). The lumen of the uterus is markedly enlarged, and the wall of the uterus is thinned. H&E = hematoxylin and eosin stain.

The incidence of hemorrhage was significantly increased in the 750 mg/kg/day group compared to the vehicle control group (Table 9). Most of the occurrences of uterine hemorrhage were moderate or marked and were characterized by large numbers of erythrocytes filling the lumen of the uterus (Figure 7A); these animals usually had dilation of the uterus as well. Less commonly, hemorrhage was characterized by extravasated erythrocytes within the parenchyma of the uterine wall.

Figure 7

Representative Images of Hemorrhage and Thrombi of the Uterus of a Female Rat in the Perinatal and Two-year Gavage Study of Black Cohosh Root Extract (H&E)

(A) Hemorrhage in the uterus of a 750 mg/kg/day rat is shown (0.5×). This cross-sectional cut reveals a blood-filled lumen in both horns of the uterus. (B) Large thrombi (asterisks) within the wall of the uterus from a 750 mg/kg/day rat are shown (1.7×). (C) A higher magnification of panel B shows organized thrombi (asterisks) and pigment (arrows), which indicate hemorrhage occurred prior to death (5×). H&E = hematoxylin and eosin stain.

Higher incidences of thrombus were present in the 250 and 750 mg/kg/day groups compared to the vehicle control group (Table 9). Histologically, thrombi were characterized by large vessels between the myometrium and perimetrium that were partially to fully occluded by abundant, homogeneous to lamellated, eosinophilic material consistent with fibrin (Figure 7B, Figure 7C); some vessels had undergone recanalization. Variable numbers of lymphocytes and macrophages were present in the vessel walls, and occasionally, basophilic mineral was observed within the thrombi. Vessels in regions with thrombi were frequently ectatic; affected uteri often had hemorrhage and dilation as concurrent changes.

Compared to the vehicle control group, a significantly increased incidence of ulcers was present in the 750 mg/kg/day group (Table 9). Ulcers were characterized by a focal to focally extensive loss of the endometrial epithelium (Figure 8). Ulcers were associated with neutrophilic inflammation, necrotic debris, and fibrin.

Figure 8

Representative Image of Ulceration of the Uterus of a Female Rat in the Perinatal and Two-year Gavage Study of Black Cohosh Root Extract (H&E)

A large area of ulceration (arrowheads) between the remaining epithelium (arrows) of the uterus from a 750 mg/kg/day rat is shown (10×). A layer of necrotic debris (asterisks) covers the area of ulceration. H&E = hematoxylin and eosin stain.

Ovary: In the ovary, the incidence of atrophy was significantly increased in the 750 mg/kg/day group compared to the vehicle control group (Table 10). Most cases across all groups were mild in severity, with little difference in the mean severity scores between the vehicle control and dosed groups. Ovarian atrophy was characterized by ovaries that had decreased numbers of corpora lutea and follicles and were smaller in size than normal (Figure 9). Marked atrophy usually corresponded to a complete lack of corpora lutea and developing follicles.

Table 10 Incidences of Nonneoplastic Lesions of the Ovary in Female Rats in the Perinatal and Two-year Gavage Study of Black Cohosh Root Extract

| 0 mg/kg/day | 75 mg/kg/day | 250 mg/kg/day | 750 mg/kg/day
Ovary | 50 | 50 | 50 | 49
Atrophy | 32** (2.1) | 39 (2.4) | 38 (2.2) | 47** (2.1)

Statistical significance for a dosed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant (p ≤ 0.05) from the vehicle control group by the Rao-Scott-adjusted Poly-3 test; **p ≤ 0.01.

^a^ Number of animals with tissue examined microscopically.

^b^ Number of animals with lesion.

^c^ Average severity grade of observed lesion in affected animals: 1 = minimal; 2 = mild; 3 = moderate; 4 = marked.

Figure 9

Representative Images of a Normal Ovary and Atrophy of the Ovary in Female Rats in the Perinatal and Two-year Gavage Study of Black Cohosh Root Extract (H&E)

(A) A normal ovary from a vehicle control rat is shown (1.2×). Even at this low magnification, numerous corpora lutea (arrows) are visible. (B) An atrophic ovary from a 750 mg/kg/day rat is shown (1.2×). The ovary is grossly smaller than that shown in panel A, and no corpora lutea are present. H&E = hematoxylin and eosin stain.

Other tissues: The incidence of bone marrow hypercellularity was significantly increased in the 750 mg/kg/day females compared to the vehicle control group (Appendix E). In males, the incidence of hemorrhage within the bone marrow was higher compared to the vehicle control group for all exposed groups and was significantly increased in the 75 and 750 mg/kg/day groups. In females, there was a significantly increased incidence of histiocyte cellular infiltrates in the lung at 750 mg/kg/day compared to the vehicle control group. The incidence of granulomatous inflammation was significantly increased in the 250 mg/kg/day females compared to the vehicle control group. In females, the incidences of cardiomyopathy in the heart were higher in all dosed groups compared to the vehicle control group; the increase was significant only in the 250 mg/kg/day group. In perinatally exposed males, the incidences of epithelial hyperplasia of the forestomach were slightly increased in all dose groups compared to the vehicle group, with statistical significance at 750 mg/kg/day. Hyperplasia was characterized by increased layers of squamous epithelium, often associated with inflammation, and in one low-dose animal with an ulcer. None of these lesions, or lesions in other tissues not described here, were considered related to BCE.

There were fewer occurrences of mammary gland hyperplasia in the 250 and 750 mg/kg/day females than in the vehicle control group. The number of mammary gland fibroadenomas and uterine stromal polyps in the 750 mg/kg/day female group was lower than in the concurrent vehicle control group and below the lower end of the range of fibroadenomas in historical controls. Significant decreases in body weight have been associated with a decreased incidence of mammary gland neoplasms in rats.^165^ Other contributions to this effect could be the marginally lower survival in this group (not statistically significant) or potential antiestrogenic activity.

## Mice

### Two-year Study Interim Evaluations (3 and 12 Months)

At the 3-month evaluation, absolute spleen weights of all BCE-dosed groups were within 10% of that of the vehicle control group (Table 11). There was a positive trend in absolute and relative spleen weights.

Table 11 Summary of Spleen Weights and Spleen-Weight-to-Body-Weight Ratios for Female Mice in the Three- and Twelve-month Interim Evaluations during the Two-year Gavage Study of Black Cohosh Root Extract^a,b^

| 0 mg/kg/day | 30 mg/kg/day | 100 mg/kg/day | 300 mg/kg/day | 1,000 mg/kg/day
n^c^ | 10 | 10 | 10 | 10 | 10
Three Months
Terminal Body Wt. (g) | 25.7 ± 0.4 | 25.4 ± 0.5 | 26.7 ± 0.8 | 25.5 ± 0.5 | 25.3 ± 0.5
Spleen
Absolute (g) | 0.080 ± 0.003* | 0.073 ± 0.004 | 0.080 ± 0.002 | 0.087 ± 0.003 | 0.086 ± 0.004
Relative (mg/g)^d^ | 3.11 ± 0.12** | 2.87 ± 0.11 | 3.03 ± 0.11 | 3.42 ± 0.13 | 3.40 ± 0.14
Twelve Months
Terminal Body Wt. (g) | 50.3 ± 2.2** | 45.2 ± 1.7* | 40.8 ± 1.5** | 38.7 ± 1.0** | 32.3 ± 0.7**
Spleen
Absolute (g) | 0.094 ± 0.003** | 0.110 ± 0.005 | 0.108 ± 0.010 | 0.116 ± 0.007* | 0.116 ± 0.005*
Relative (mg/g) | 1.90 ± 0.07** | 2.45 ± 0.14* | 2.63 ± 0.20** | 3.00 ± 0.17** | 3.59 ± 0.14**

Statistical significance for a dosed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ Data are presented as mean ± standard error.

^b^ Statistical analysis performed by the Jonckheere (trend) and the Williams or Dunnett (pairwise) tests.

^c^ Number of animals examined.

^d^ Relative organ weights (organ-weight-to-body-weight ratios) are given as mg organ weight/g body weight.

At the 12-month evaluation, absolute spleen weights of all dosed groups were higher than that of the vehicle control group (Table 11). The largest differences were in the 300 and 1,000 mg/kg/day groups, which both had significantly increased absolute mean spleen weights that were approximately 23% higher than that of the vehicle control group. Relative spleen weights increased with increasing dose and were significantly increased for all dosed groups compared to that of the vehicle control group. Mean body weights of dosed groups at the 12-month evaluation decreased with increasing dose, and the spleen weight changes were considered related to BCE administration.

The frequency of micronucleated erythrocytes was evaluated in peripheral blood samples obtained at the 3- and 12-month evaluations (Appendix D). At the 3-month evaluation, a significant, dose-related increase in micronucleated erythrocytes was observed (Table 12). To determine whether the responses seen after 3 months of BCE administration increased, decreased, or remained the same after a full year, peripheral blood erythrocytes were evaluated after 12 months of dosing. Again, there was a significant, dose-related increase in the frequencies of micronucleated erythrocytes in these mice, with a magnitude of response similar to the 3-month evaluation (Table 12). No significant changes were observed in the percentage of immature erythrocytes (% PCE) in the BCE-dosed mice at either evaluation.

Table 12 Frequency of Micronuclei in Peripheral Blood Erythrocytes of Female Mice in the Three- and Twelve-month Interim Evaluations during the Two-year Gavage Study of Black Cohosh Root Extract^a^

| Number of Mice with Erythrocytes Scored | Micronucleated PCEs/1,000 PCEs^b^ | P Value^c^ | Micronucleated NCEs/1,000 NCEs^b^ | P Value^c^ | PCEs (%)^b^ | P Value^c^
Three Months
Dose (mg/kg/day)
0 | 5 | 2.050 ± 0.119 | | 1.056 ± 0.018 | | 1.585 ± 0.101
30 | 5 | 2.080 ± 0.221 | 1.0000 | 1.080 ± 0.013 | 0.3328 | 1.639 ± 0.117 | 0.8229
100 | 5 | 2.420 ± 0.189 | 0.8277 | 1.370 ± 0.045 | <0.001 | 1.826 ± 0.133 | 0.7443
300 | 5 | 3.250 ± 0.099 | 0.0404 | 1.908 ± 0.052 | <0.001 | 1.695 ± 0.116 | 0.7906
1,000 | 5 | 5.530 ± 0.485 | 0.0012 | 2.890 ± 0.046 | <0.001 | 1.638 ± 0.208 | 0.8121
Trend^d^ | | p < 0.001 | | p < 0.001 | | p = 0.6474
Twelve Months
Dose (mg/kg/day)
0 | 5 | 1.870 ± 0.116 | | 1.002 ± 0.035 | | 1.801 ± 0.167
30 | 5 | 2.100 ± 0.106 | 0.8271 | 1.074 ± 0.036 | 1.0000 | 1.880 ± 0.230 | 0.8948
100 | 5 | 2.090 ± 0.128 | 0.8271 | 1.378 ± 0.118 | 0.1174 | 2.081 ± 0.145 | 0.8261
300 | 5 | 3.950 ± 0.695 | 0.0060 | 1.892 ± 0.196 | 0.0070 | 1.928 ± 0.348 | 0.8697
1,000 | 5 | 5.000 ± 0.359 | 0.0011 | 2.641 ± 0.228 | <0.001 | 2.439 ± 0.305 | 0.2152
Trend | | p < 0.001 | | p < 0.001 | | p = 0.1440

PCE = polychromatic erythrocyte; NCE = normochromatic erythrocyte.

^a^ Study was performed at Integrated Laboratory Systems, LLC.

^b^ Data are presented as mean ± standard error.

^c^ Pairwise comparisons with the vehicle control group performed using the Williams or Dunn test (p ≤ 0.025).

^d^ Dose-related trends evaluated by linear regression or the Jonckheere test (p ≤ 0.025).

A complete blood count, bone marrow cell count, and bone marrow cytological evaluation were performed at the 3- and 12-month evaluations. At 3 months, the mean cell volume (MCV) and mean cell hemoglobin (MCH) were significantly increased in all BCE-dosed groups relative to the vehicle control group (Table 13). The erythrocyte count showed a negative trend with a significant pairwise decrease in the 1,000 mg/kg/day group relative to the vehicle control group. Additionally, the total white blood cell, neutrophil, lymphocyte, and monocyte counts were significantly decreased in various dosed groups. At the 12-month evaluation, the hematocrit and erythrocyte counts were significantly decreased in all dosed groups, and hemoglobin was significantly decreased in the 300 and 1,000 mg/kg/day groups relative to the vehicle control group (Table 13). The MCV and MCH were also significantly increased in most dosed groups relative to the vehicle control group. The leukogram changes observed at the 3-month evaluation were ameliorated by 12 months.

Table 13 Summary of Select Hematology Data for Female Mice in the Three- and Twelve-month Interim Evaluations during the Two-year Gavage Study of Black Cohosh Root Extract^a,b^

| 0 mg/kg/day | 30 mg/kg/day | 100 mg/kg/day | 300 mg/kg/day | 1,000 mg/kg/day
Three Months^c^ | 9 | 10 | 10 | 10 | 10
Hematocrit (%) | 55.6 ± 1.2 | 56.3 ± 1.0 | 57.0 ± 1.6 | 56.5 ± 1.6 | 53.4 ± 1.0
Hemoglobin (g/dL) | 17.1 ± 0.3 | 17.5 ± 0.3 | 17.7 ± 0.5 | 17.7 ± 0.5 | 16.4 ± 0.3
Erythrocytes (10^6^/µL) | 11.42 ± 0.21** | 11.42 ± 0.21 | 11.24 ± 0.30 | 10.76 ± 0.27 | 9.73 ± 0.19**
Reticulocytes (10^3^/µL) | 272.8 ± 11.8 | 275.7 ± 15.9 | 293.8 ± 14.5 | 282.2 ± 10.5 | 255.5 ± 17.6
Mean Cell Volume (fL) | 48.7 ± 0.2** | 49.4 ± 0.2* | 50.7 ± 0.2** | 52.5 ± 0.3** | 54.9 ± 0.3**
Mean Cell Hemoglobin (pg) | 15.0 ± 0.1** | 15.3 ± 0.0** | 15.7 ± 0.0** | 16.5 ± 0.2** | 16.9 ± 0.1**
Mean Cell Hemoglobin Concentration (g/dL) | 30.8 ± 0.2 | 31.1 ± 0.1 | 31.1 ± 0.1 | 31.4 ± 0.3 | 30.7 ± 0.1
White Blood Cells (10^3^/µL) | 4.45 ± 0.45** | 3.95 ± 0.31 | 3.25 ± 0.19 | 3.61 ± 0.43 | 2.85 ± 0.36**
Neutrophils (10^3^/µL) | 0.62 ± 0.07** | 0.51 ± 0.06 | 0.41 ± 0.04* | 0.38 ± 0.04* | 0.42 ± 0.12**
Lymphocytes (10^3^/µL) | 3.66 ± 0.39** | 3.28 ± 0.25 | 2.71 ± 0.15 | 3.14 ± 0.39 | 2.32 ± 0.25**
Monocytes (10^3^/µL) | 0.09 ± 0.01** | 0.07 ± 0.01 | 0.08 ± 0.02 | 0.04 ± 0.01** | 0.05 ± 0.01**
Twelve Months | 10 | 10 | 10 | 10 | 10
Hematocrit (%) | 52.5 ± 0.6** | 51.2 ± 0.5* | 51.3 ± 0.6* | 49.6 ± 0.6** | 50.1 ± 0.4**
Hemoglobin (g/dL) | 15.4 ± 0.2** | 15.3 ± 0.1 | 15.2 ± 0.2 | 14.8 ± 0.2* | 14.9 ± 0.1*
Erythrocytes (10^6^/µL) | 10.34 ± 0.10** | 10.02 ± 0.10* | 9.77 ± 0.16** | 9.22 ± 0.13** | 9.00 ± 0.08**
Reticulocytes (10^3^/µL) | 247.4 ± 16.6 | 290.0 ± 25.0 | 276.6 ± 14.9 | 230.8 ± 15.0 | 256.9 ± 22.5
Mean Cell Volume (fL) | 50.7 ± 0.3** | 51.1 ± 0.2 | 52.6 ± 0.4** | 53.8 ± 0.3** | 55.7 ± 0.2**
Mean Cell Hemoglobin (pg) | 14.9 ± 0.1** | 15.2 ± 0.1* | 15.6 ± 0.1** | 16.0 ± 0.1** | 16.6 ± 0.1**
Mean Cell Hemoglobin Concentration (g/dL) | 29.4 ± 0.1 | 29.8 ± 0.2 | 29.7 ± 0.2 | 29.7 ± 0.2 | 29.8 ± 0.1
White Blood Cells (10^3^/µL) | 4.02 ± 0.35 | 3.65 ± 0.27 | 3.39 ± 0.23 | 3.89 ± 0.28 | 3.58 ± 0.44
Neutrophils (10^3^/µL) | 0.80 ± 0.07 | 0.57 ± 0.09* | 0.57 ± 0.04 | 0.66 ± 0.04 | 0.71 ± 0.09
Lymphocytes (10^3^/µL) | 3.05 ± 0.30 | 2.95 ± 0.19 | 2.75 ± 0.22 | 3.07 ± 0.23 | 2.74 ± 0.35
Monocytes (10^3^/µL) | 0.10 ± 0.03 | 0.10 ± 0.03 | 0.06 ± 0.02 | 0.11 ± 0.01 | 0.06 ± 0.01

Statistical significance for a dosed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ Data are presented as mean ± standard error.

^b^ Statistical analysis performed by the Jonckheere (trend) and the Shirley or Dunn (pairwise) tests.

^c^ Number of animals examined at each evaluation.

No changes were observed in the bone marrow cell count or bone marrow myeloid:erythroid ratio of the BCE-dosed groups relative to the vehicle control groups (Appendix E). Cytological evaluation of the erythroid, myeloid, and megakaryocyte cell lines revealed mild dysplasia in a low number of metarubricytes at both the 3- and 12-month evaluations. These abnormal metarubricytes were observed with higher frequency in the 100, 300, and 1,000 mg/kg/day groups relative to the vehicle control group (Table 14; Figure 10). Observed dysplastic features included the following: multilobulated nuclei, micronuclei, nuclear-to-cytoplasmic asynchrony, gigantism, and nuclear fragmentation. In relation to the absolute erythroid precursors, the percentages of abnormal metarubricytes at 3 and 12 months ranged from 0.5 to 10.8, depending on the dose (Table 14). The abnormal metarubricytes were not included in the absolute erythroid precursor counts.

Table 14 Summary of Bone Marrow Cytology Data for Female Mice in the Three- and Twelve-month Interim Evaluations during the Two-year Gavage Study of Black Cohosh Root Extract

| 0 mg/kg/day | 30 mg/kg/day | 100 mg/kg/day | 300 mg/kg/day | 1,000 mg/kg/day
n^a^ | 10 | 10 | 10 | 10 | 10
Three Months
Incidence of Abnormal Metarubricytes | 0/10 | 0/10 | 3/10 | 6/10 | 9/10
Min # Abnormal Metarubricytes^b^ | 0 | 0 | 1 | 1 | 5
Max # Abnormal Metarubricytes^b^ | 0 | 0 | 3 | 3 | 15
Mean # Abnormal Metarubricytes | 0 | 0 | 1.67 | 1.83 | 10.67
Mean # Erythroid Precursors^c^ | 0 | 0 | 179.33 | 161.67 | 161.78
Min % Abnormal Metarubricytes^d^ | 0 | 0 | 0.5 | 0.5 | 3.7
Max % Abnormal Metarubricytes^d^ | 0 | 0 | 1.7 | 1.7 | 8.4
Twelve Months
Incidence of Abnormal Metarubricytes | 0/10 | 0/10 | 2/10 | 4/10 | 10/10
Min # Abnormal Metarubricytes | 0 | 0 | 1 | 1 | 2
Max # Abnormal Metarubricytes | 0 | 0 | 3 | 4 | 24
Mean # Abnormal Metarubricytes | 0 | 0 | 2.00 | 2.25 | 6.60
Mean # Erythroid Precursors | 0 | 0 | 173.50 | 170.50 | 152.00
Min % Abnormal Metarubricytes | 0 | 0 | 0.6 | 0.6 | 1.4
Max % Abnormal Metarubricytes | 0 | 0 | 1.7 | 2.3 | 10.8

No trend or pairwise statistical tests were performed on these data.

Min = minimum; # = number; max = maximum; % = percent.

^a^ Number of animals examined at each evaluation.

^b^ Number of abnormal metarubricytes counted in the bone marrow 500-cell differential cell count.

^c^ Mean of number of erythroid precursors counted in the bone marrow 500-cell differential cell count from animals with abnormal metarubricytes.

^d^ 100 × (number of abnormal rubricytes)/(number of erythroid precursors from animals with abnormal metarubricytes).

Figure 10

Representative Images of Abnormal Metarubricytes in the Bone Marrow of a Female Mouse in the Two-year Gavage Study of Black Cohosh Root Extract (Wright’s Giemsa Stain)

(A) Several binucleated metarubricytes (arrows) in the bone marrow of a 1,000 mg/kg/day mouse is shown (50×). (B) Several metarubricytes displaying nuclear-to-cytoplasmic asynchrony are present (arrows) in the bone marrow of a 1,000 mg/kg/day mouse (50×). Features of nuclear-to-cytoplasmic asynchrony include immature nuclei (more open chromatin) relative to a more mature-looking cytoplasm (pinkish in color due to hemoglobin accumulation).

#### Histopathology

This section describes the statistically significant or biologically noteworthy changes in the incidence of nonneoplastic lesions of the spleen and bone marrow.

Three-month interim evaluation: There were no significant differences in the incidences of lesions between the vehicle control group and BCE-dosed groups at the 3-month interim evaluation; only the spleen and bone marrow were examined histologically at this evaluation (Appendix E).

Twelve-month interim evaluation: At the 12-month interim evaluation, only the spleen and bone marrow were examined histologically. Compared to the vehicle control group, there was a significantly increased incidence of hematopoietic cell proliferation in the spleens of the 100 mg/kg/day group that was considered sporadic, and not related to BCE administration; no effect was observed at 3 months. There were no significant differences in the incidences of bone marrow lesions between the vehicle control group and BCE-dosed groups (Appendix E).

### Two-year Study Final Evaluations

Estimates of 2-year survival probabilities for female mice are shown in Table 15 and in the Kaplan-Meier survival curve (Figure 11). Survival of all BCE-dosed groups was similar to that of the vehicle control group.

Table 15 Summary of Survival of Female Mice in the Two-year Gavage Study of Black Cohosh Root Extract

| 0 mg/kg/day | 30 mg/kg/day | 100 mg/kg/day | 300 mg/kg/day | 1,000 mg/kg/day
Animals Initially in Study | 50 | 50 | 50 | 50 | 50
Moribund | 4 | 2 | 3 | 3 | 6
Natural Deaths | 6 | 9 | 3 | 7 | 6
Accidental Deaths | 0 | 0 | 0 | 1 | 0
Animals Surviving to Study Termination | 40 | 39 | 44 | 39 | 38
Percent Probability of Survival at Study Termination^a^ | 80.0% | 80.0% | 88.0% | 79.6% | 76.0%
Mean Survival (Days)^b^ | 703.2 ± 9.7 | 714.8 ± 5.9 | 720.9 ± 3.5 | 707.0 ± 7.3 | 692.2 ± 14.4
Survival Analysis^c^ | p = 0.389 | p = 1.000N | p = 0.393N | p = 1.000 | p = 0.785

^a^ Kaplan-Meier determinations.

^b^ Mean of all deaths (uncensored, censored, and study termination) ± standard error.

^c^ The result of the Tarone trend test is in the vehicle control group column, and the results of the Cox log-rank pairwise comparisons to the vehicle control group are in the dosed group columns. A negative trend or lower mortality in a dosed group is indicated by N.

Figure 11

Kaplan-Meier Survival Curves for Female Mice Administered Black Cohosh Root Extract in the Two-year Gavage Study

Mean body weights of the 100, 300, and 1,000 mg/kg/day females were ≤90% of that of the vehicle control group beginning on study day 141 and continued to decrease throughout the remainder of the study (Table 16; Figure 12). Mean body weight of the 30 mg/kg/day females remained within 12% of that of the vehicle control group throughout the study. At study termination, mean body weights of the 30, 100, 300, and 1,000 mg/kg/day groups were 91%, 82%, 75%, and 60%, respectively, of that of the vehicle control group.

Table 16 Summary of Survival and Mean Body Weights of Female Mice in the Two-year Gavage Study of Black Cohosh Root Extract

Study Day^a^ | 0 mg/kg/day | | 30 mg/kg/day | | | 100 mg/kg/day | | | 300 mg/kg/day | | | 1,000 mg/kg/day
Study Day^a^ | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors
1 | 17.6 | 50 | 18.0 | 102.0 | 50 | 17.7 | 100.4 | 50 | 17.8 | 100.9 | 50 | 17.9 | 101.3 | 50
8 | 18.1 | 50 | 18.4 | 101.5 | 50 | 18.7 | 103.3 | 50 | 18.7 | 103.3 | 50 | 18.8 | 103.9 | 50
15 | 19.1 | 50 | 19.4 | 101.2 | 50 | 19.6 | 102.5 | 50 | 19.8 | 103.6 | 50 | 19.7 | 103.0 | 50
22 | 19.9 | 50 | 20.1 | 100.7 | 50 | 20.4 | 102.2 | 50 | 20.6 | 103.5 | 50 | 20.8 | 104.3 | 50
29 | 20.7 | 50 | 20.7 | 100.0 | 50 | 20.7 | 100.2 | 50 | 21.3 | 102.9 | 50 | 21.3 | 103.1 | 50
36 | 21.5 | 50 | 21.4 | 99.6 | 50 | 21.4 | 99.7 | 50 | 22.0 | 102.3 | 50 | 22.1 | 102.9 | 50
43 | 22.2 | 50 | 22.2 | 100.1 | 50 | 22.0 | 99.1 | 50 | 22.7 | 101.9 | 50 | 22.8 | 102.4 | 50
50 | 22.8 | 50 | 22.5 | 98.5 | 50 | 22.5 | 98.6 | 50 | 23.3 | 102.2 | 50 | 22.9 | 100.4 | 50
57 | 23.6 | 50 | 23.0 | 97.4 | 50 | 23.1 | 97.6 | 50 | 23.7 | 100.3 | 50 | 23.8 | 100.9 | 50
64 | 24.2 | 50 | 23.7 | 98.1 | 50 | 23.9 | 98.7 | 50 | 24.2 | 100.1 | 50 | 24.5 | 101.4 | 50
71 | 24.7 | 50 | 24.2 | 98.0 | 50 | 24.5 | 98.9 | 50 | 25.5 | 103.1 | 50 | 24.9 | 100.8 | 50
78 | 25.3 | 50 | 24.5 | 96.7 | 50 | 24.7 | 97.4 | 50 | 25.3 | 99.9 | 50 | 25.4 | 100.1 | 50
85 | 26.2 | 50 | 25.4 | 96.9 | 50 | 25.5 | 97.2 | 50 | 25.9 | 98.7 | 50 | 25.9 | 98.5 | 50
113 | 29.0 | 50 | 27.4 | 94.5 | 50 | 27.1 | 93.4 | 50 | 26.4 | 91.2 | 50 | 26.7 | 92.1 | 50
141 | 32.7 | 50 | 29.6 | 90.7 | 50 | 29.3 | 89.6 | 50 | 28.6 | 87.7 | 50 | 27.8 | 85.2 | 50
169 | 34.7 | 50 | 32.8 | 94.6 | 50 | 31.3 | 90.1 | 50 | 30.5 | 88.1 | 50 | 29.2 | 84.3 | 50
197 | 37.1 | 50 | 34.1 | 92.1 | 50 | 31.6 | 85.3 | 50 | 30.9 | 83.5 | 50 | 30.0 | 80.9 | 49
225 | 39.9 | 50 | 36.6 | 91.8 | 50 | 34.1 | 85.4 | 50 | 32.9 | 82.4 | 50 | 31.1 | 77.8 | 49
253 | 41.2 | 50 | 37.9 | 92.0 | 50 | 35.1 | 85.2 | 50 | 34.2 | 82.9 | 50 | 31.9 | 77.3 | 49
281 | 43.5 | 50 | 39.7 | 91.3 | 50 | 36.2 | 83.4 | 50 | 35.5 | 81.6 | 50 | 31.9 | 73.4 | 49
309 | 47.3 | 50 | 42.8 | 90.4 | 50 | 38.3 | 80.9 | 50 | 36.9 | 78.0 | 50 | 32.8 | 69.4 | 49
337 | 47.8 | 50 | 43.6 | 91.2 | 50 | 38.8 | 81.1 | 50 | 37.5 | 78.5 | 50 | 33.1 | 69.3 | 49
365 | 50.1 | 50 | 44.6 | 89.0 | 50 | 40.7 | 81.2 | 50 | 39.1 | 78.1 | 50 | 34.4 | 68.7 | 49
393 | 50.2 | 50 | 45.6 | 90.8 | 50 | 41.8 | 83.3 | 50 | 39.1 | 77.9 | 50 | 34.1 | 68.0 | 48
421 | 52.2 | 50 | 46.5 | 89.0 | 50 | 42.2 | 80.9 | 50 | 39.4 | 75.4 | 50 | 34.4 | 65.8 | 48
449 | 53.5 | 50 | 47.9 | 89.5 | 50 | 44.0 | 82.2 | 50 | 40.6 | 75.9 | 50 | 34.9 | 65.1 | 48
477 | 55.0 | 49 | 49.7 | 90.3 | 50 | 45.8 | 83.2 | 50 | 42.2 | 76.6 | 49 | 36.1 | 65.7 | 47
505 | 57.3 | 47 | 50.6 | 88.3 | 50 | 46.5 | 81.1 | 50 | 42.6 | 74.2 | 49 | 36.4 | 63.5 | 47
533 | 57.0 | 46 | 50.4 | 88.4 | 50 | 46.6 | 81.7 | 50 | 42.4 | 74.4 | 49 | 35.7 | 62.6 | 47
561 | 58.5 | 46 | 51.5 | 88.2 | 49 | 47.4 | 81.1 | 50 | 43.4 | 74.2 | 49 | 36.7 | 62.8 | 46
589 | 57.1 | 45 | 51.6 | 90.3 | 48 | 46.8 | 82.0 | 50 | 43.5 | 76.2 | 48 | 36.2 | 63.5 | 45
617 | 57.7 | 45 | 51.5 | 89.3 | 47 | 46.8 | 81.1 | 49 | 42.6 | 73.9 | 47 | 35.3 | 61.1 | 44
645 | 58.1 | 45 | 52.3 | 89.9 | 46 | 47.2 | 81.2 | 49 | 43.4 | 74.6 | 46 | 35.8 | 61.6 | 44
673 | 58.8 | 44 | 53.1 | 90.3 | 45 | 47.7 | 81.1 | 47 | 44.3 | 75.3 | 41 | 36.3 | 61.7 | 42
701 | 58.2 | 42 | 53.1 | 91.2 | 44 | 47.6 | 81.7 | 44 | 43.6 | 74.9 | 39 | 35.5 | 61.0 | 40
EOS | 56.1 | 40 | 51.2 | 91.2 | 39 | 45.7 | 81.5 | 44 | 42.0 | 74.8 | 39 | 33.7 | 60.0 | 38

No trend or pairwise statistical tests were performed on these data.

EOS = end of study.

^a^ Study day 1 is the day animals were placed on study.

Figure 12

Growth Curves for Female Mice in the Two-year Gavage Study of Black Cohosh Root Extract

No clinical observations in dosed groups of mice were considered related to BCE administration (Appendix E).

#### Histopathology

This section describes the statistically significant or biologically noteworthy changes in the incidences of nonneoplastic lesions of the liver and thyroid gland in female mice. No neoplasms were considered related to the administration of BCE in female mice.

Liver: The incidence of necrosis in the liver was significantly increased in the 1,000 mg/kg/day group relative to the vehicle control group (Table 17). Histologically, liver necrosis (Figure 13A) did not have a distinctive lobular pattern; instead, it consisted of randomly scattered focal areas of coagulative necrosis characterized by brightly eosinophilic cytoplasm and shrunken, pyknotic nuclei (Figure 13B). Less commonly, individual necrotic cells were scattered within the hepatic parenchyma. Areas of necrosis, as well as individual necrotic cells (Figure 13C), were often associated with inflammatory cells. Necrosis that was considered secondary to a neoplasm was not recorded separately.

Table 17 Incidences of Nonneoplastic Lesions of Select Organs in Female Mice in the Two-year Gavage Study of Black Cohosh Root Extract

| 0 mg/kg/day | 30 mg/kg/day | 100 mg/kg/day | 300 mg/kg/day | 1,000 mg/kg/day
Liver^a^ | 50 | 50 | 50 | 50 | 50
Necrosis^b^ | 2** (1.0)^c^ | 0 | 1 (1.0) | 1 (1.0) | 8* (1.1)
Thyroid Gland | 50 | 50 | 49 | 49 | 50
Follicle, dilation | 0** | 1 (2.0) | 1 (1.0) | 1 (1.0) | 5* (1.4)

Statistical significance for a dosed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05 by the Poly-3 test; **p ≤ 0.01.

^a^ Number of animals examined microscopically.

^b^ Number of animals with lesion.

^c^ Average severity grade of observed lesion in affected animals: 1 = minimal; 2 = mild; 3 = moderate; 4 = marked.

Figure 13

Representative Images of Necrosis in the Liver of a Female Mouse in the Two-year Gavage Study of Black Cohosh Root Extract (H&E)

(A) Necrosis in the liver of a 1,000 mg/kg/day mouse is shown (10×). Several small areas of hepatocellular necrosis (arrows), as well as scattered individual necrotic cells (circles), are indicated. (B) A higher magnification of the liver from panel A is shown (20×). Within the necrotic tissue, the outlines of swollen cells containing pale eosinophilic flocculant material (arrows) are apparent. These necrotic cells lack normal cytoplasmic detail, and some are devoid of a nucleus, while others contain only a small pyknotic nucleus. (C) A higher magnification of a circled area from panel A shows an individual necrotic cell with associated inflammatory cells (circle; 40×). H&E = hematoxylin and eosin stain.

Thyroid gland: The incidence of follicle dilation in the thyroid gland was significantly increased in the 1,000 mg/kg/day group relative to the vehicle control group (Table 17). This change was focal, not diffuse, and was characterized by one or more follicles that were several times larger than normal follicles and caused compression of the adjacent follicles (Figure 14). The epithelium lining the follicles was typically flattened, and there was no evidence of papillary projections or hyperplasia. This change is often seen in the thyroid gland of older mice and is associated with changes in thyroid gland function as the animals age.^166^

Figure 14

Representative Images of Follicular Dilation in the Thyroid of Female Mice in the Two-year Gavage Study of Black Cohosh Root Extract (H&E)

Dilated follicles are not uncommon in the thyroid glands of mice; dilation of the follicle was not recorded unless the follicles were much larger than normal. (A) In the thyroid gland of a vehicle control mouse, some follicles at the periphery of the gland (arrows) are larger than those toward the center of the gland (10×). Follicle dilation was not recorded. (B) Thyroid follicle dilation in a 1,000 mg/kg/day mouse is shown (10×). There are fewer follicles than in panel A, and those that are present are large and lined by flattened epithelial cells. (C) Another example of thyroid follicle dilation appears in a 1,000 mg/kg/day mouse (10×). Two very large follicles are present within the gland (asterisks). H&E = hematoxylin and eosin stain.

Other tissues: There was a significant increase in the incidence of lymphoid hyperplasia in the mandibular lymph node in the 100 and 1,000 mg/kg/day groups relative to the vehicle control group (Appendix E), but this was not considered related to the administration of BCE because of the lack of a consistent response and its inherent variability. Lymphoid hyperplasia was characterized by increased numbers of mature small lymphocytes in the paracortical areas or an increased size and/or number of follicles compared with vehicle control mice.

The incidences of acute inflammation in the uterus and vagina were greater in the vehicle control group than in most dosed groups. Acute inflammation consisted primarily of neutrophils, although occasionally lymphocytes or macrophages were observed. Inflammation can normally be found in the vagina of mice during estrus. In animals in which inflammation was diagnosed, however, there were unusually large numbers of neutrophils, clusters of neutrophils forming pustule-like lesions in the epithelium, or large aggregates of neutrophils in the lumen—changes that are not characteristic of the normal presence of neutrophils found in the vagina during estrus. Inflammation in the vagina of B6C3F1 mice is a common finding, with one article listing the incidence at approximately 40% at 24 months of age.^167^

There was a significant increase in the incidence of squamous hyperplasia of the vaginal epithelium in the 100 mg/kg/day group relative to the vehicle control group. This finding was considered sporadic and not related to BCE administration.

## Genetic Toxicology

In addition to interim micronuclei evaluations of peripheral erythrocytes in female mice (Table 12), two different lots of BCE were tested in two independent bacterial mutagenicity assays in multiple strains of bacteria, with and without induced rodent liver S9 mixes. Results were negative in the initial assay that used both hamster and rat liver S9 over a dose range of 100–10,000 µg/plate in six strains of Salmonella typhimurium or a dose range of 3.3–10,000 µg/plate in S. typhimurium TA97 (Appendix D). In the second study, the BCE lot used in the NTP in vivo rodent studies was tested at doses up to 6,000 µg/plate in three strains of bacteria, with and without induced rat liver S9; this sample was not mutagenic in two strains of bacteria, S. typhimurium TA100 and Escherichia coli WP2 uvrA (pKM101), but it was judged to be equivocal in S. typhimurium TA98 in the presence of induced rat liver S9 (Appendix D).^168^

Data from all NTP genetic toxicity tests with BCE are available in the NTP Chemical Effects in Biological Systems database: https://doi.org/10.22427/NTP-DATA-TR-603.^164^