# Materials and Methods

## Procurement and Characterization

### Black Cohosh Root Extract

Black cohosh root extract (BCE) was obtained from PlusPharma, Inc. (Vista, CA) in a single lot (3012782). According to the manufacturer’s certificate of analysis, lot 3012782 was a 50% aqueous ethanolic extract standardized to 7.8% (w/w) total triterpene glycosides. Identity, purity, and stability analyses were conducted by the study laboratory Battelle (Columbus, OH). Reports on analyses performed in support of the BCE studies are on file at the National Institute of Environmental Health Sciences (NIEHS).

The BCE test lot was a light-brown powder. It was confirmed to be authentic black cohosh by multiple laboratories using high-performance thin-layer chromatography and DNA barcoding. Fourier transform infrared (IR) spectroscopy detected the presence of phenolic compounds as well as plant components such as sugars, terpenes, and glycosides. Proton-induced X-ray emission spectroscopy analysis conducted by Element Analysis Corporation (Lexington, KY) indicated that the BCE was composed almost entirely of carbon (69.5%), hydrogen (11.7%), and oxygen (15.4%). Potassium (2.5%), magnesium (0.3%), and calcium (0.3%) were also detected. Water content in lot 3012782 was determined to be <7.9% via Karl Fisher analysis (Prevalere Life Sciences, Inc., Whitesboro, NY) and weight loss on drying.

Analysis of the extract by liquid chromatography (LC) coupled with quadrupole time-of-flight mass spectrometry (MS) or quadrupole ion trap MS identified multiple constituents, including caffeic acid, ferulic acid, isoferulic acid, actein, 23-epi-26-deoxyactein (27-deoxyactein), cimifugin, allocryptopine, cimicifugoside H-1, cimiracemoside C, 26-deoxycimicifugoside, magnoflorine, and prim-o-glucosylcimifugin. Quantitation of analytes by LC coupled with tandem MS showed that the extract contained (w/w) 0.28% caffeic acid, 0.04% ferulic acid, 0.70% isoferulic acid, 0.47% actein, 2.09% 23-epi-26-deoxyactein (27-deoxyactein), 2.13% cimiracemoside C, 0.08% 26-deoxycimicifugoside, and 0.01% magnoflorine. Cimifugin, prim-o-glucosylcimifugin, allocryptopine, and cimifugoside H-1 were not quantifiable and were estimated to be <0.01% of the extract. The measured constituents accounted for approximately 5.8% of the total extract weight.

An aliquot of the test lot was evaluated for environmental contaminants by Covance Laboratories, Inc. (Madison, WI) (Appendix A). The heavy metals arsenic, cadmium, and lead were present at low levels, below the threshold limits for botanical dietary supplements.^119,120^ Of >300 pesticides screened, only chlorpropham and 2-phenylphenol were detected, and these were present at concentrations below the lowest respective U.S. Environmental Protection Agency residue tolerance levels.^121,122^ Aflatoxins B_1_, B_2_, G_1_, and G_2_ and the pesticide imazilil could not be accurately detected due to matrix interferences. All other pesticides tested were determined to be below the limits of quantitation.

A comparison of high-performance liquid chromatography (HPLC)-charged aerosol detection chromatographic profiles of BCE lot 3012782 with root extract reference material and a black cohosh product available to the public in the United States showed that the chemical profiles were similar.

Accelerated stability studies were conducted, using isoferulic acid as the marker, by storing samples of lot 3012782 in amber glass bottles for 14 days at frozen (−20°C), refrigerated (5°C), room (25°C), and elevated (60°C) temperatures. Stability was confirmed for at least 14 days at ≤25°C. Further details identifying the test lot as BCE, as well as a thorough description of its composition, are available in a separate publication by Waidyanatha et al.^123^

Six plastic bags of the BCE test lot were originally received. Each was double bagged and rolled for 5 minutes to homogenize. All bags were then transferred to 4 L plastic bottles. Samples were removed and stored to serve as analytical standards, reference standards, and an archive sample. The remaining bulk test article was sealed and stored at room temperature. Reanalysis of the bulk chemical, using isoferulic acid as the marker, was performed once (mice) or three times (rats) before the start of the study, four times during the study, and one time after study termination using HPLC with ultraviolet (UV) detection. No degradation of the bulk test article was detected by analysis of the marker constituent, comparison of the constituent profile with frozen reference material, or the appearance of the bulk material.

### Methylcellulose

Methylcellulose used to make the 0.5% aqueous vehicle for gavage formulations was obtained from Spectrum (Gardena, CA) in two lots (2CB0045 and 2AJ0439). The identity of methylcellulose was confirmed by the study laboratory using IR spectroscopy. Methoxy content of both lots was measured by Galbraith Laboratories, Inc. (Knoxville, TN) to determine purity. Purity reanalysis was conducted at 6-month intervals over the course of the study. Deionized tap water was used to make the 0.5% (w/v) aqueous methylcellulose vehicle for gavage formulations.

## Preparation and Analysis of Dose Formulations

Dose formulations were prepared at the study laboratory by mixing the BCE test lot with 0.5% aqueous methylcellulose following the protocols outlined in Appendix A. For the rat study, formulations were prepared at 0, 15, 50, and 150 mg/mL. For the mouse study, formulations were prepared at 0, 3, 10, 30, and 100 mg/mL.

The homogeneity and stability of the dose formulations were determined by the study laboratory. Isoferulic acid was used as the marker for BCE formulation analysis. Homogeneity was evaluated using 3, 20, 100, and 200 mg/mL formulations and was confirmed at these doses. Stability of the 3, 30, and 100 mg/mL formulations was investigated using marker constituents actein, 27-deoxyactein, isoferulic acid, or cimiracemoside C prior to and following study termination. Stability of the 3, 30, and 100 mg/mL dose formulations was confirmed for up to 42 days in sealed, refrigerated, amber glass bottles. In addition, the 3, 30, and 100 mg/mL dose formulations were stable under simulated animal room conditions for at least 3 hours. The dose formulations were stored in sterile, clear glass, straight-sided bottles under inert headspace at 2°C–8°C (refrigerated).

The dose formulations were used within 42 days during the first 11 months of the studies. Before dose administration on April 13, 2013, unidentified particles resembling mold were observed in the 15 mg/mL rat dose formulation and in the 3 and 10 mg/mL mouse dose formulation. To determine whether storing the formulation frozen would prevent mold growth, an experiment was conducted by storing formulations at approximately −20°C in polycarbonate jars for 26 days. The frozen formulations were then thawed and analyzed using HPLC/UV. All dose formulations were within 10% of the target concentrations, and the results indicated no differences between refrigerated and frozen samples. Following this finding, subsequent dose formulations were used within 21 days and included backup formulations that were stored frozen. There were no further reports of mold growth in the dose formulations during the 2-year studies.

## Animal Source

Time-mated (F_0_) female Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) rats were obtained from Envigo (formerly Harlan Laboratories, Inc., Indianapolis, IN). Male and female B6C3F1/N mice were obtained from the National Toxicology Program (NTP) colony maintained by Taconic Biosciences, Inc. (Germantown, NY).

## Animal Welfare

Animal care and use were in accordance with the Public Health Service Policy on Humane Care and Use of Animals. All animal studies were conducted in an animal facility accredited by AAALAC International. Studies were approved by the Battelle (Columbus, OH) Animal Care and Use Committee and conducted in accordance with all relevant National Institutes of Health (NIH) and NTP animal care and use policies and applicable federal, state, and local regulations and guidelines.

## Two-year Studies

### Dose Selection Rationale

Dose selection was based on findings from the 3-month repeat-dose studies, which observed no effect on survival and marginal effects on body weight (within 10% of control values) in female Wistar Han rats and B6C3F1/N mice.^55^ As the primary toxicity observed was mild hematological effects, a similar dose range up to 1,000 mg BCE/kg body weight/day (mg/kg/day) was used for the mouse chronic study. Perinatal exposure was included in the rat study because women use BCE for general female health, which may include use during pregnancy. Males were not dosed postweaning but were maintained in the study to evaluate potential in utero effects. Because preliminary data indicated mortality of pups from dams administered 1,000 mg/kg/day via gavage throughout gestation and lactation, the highest dose administered to rats was 750 mg/kg/day (NTP, unpublished).

### Study Design for Rats

F_0_ female rats were 12–15 weeks old upon receipt. Evidence of mating is defined as gestation day (GD) 1; F_0_ females were received on GD 2 and held for 4 days. F_0_ females were randomly assigned to one of four dose groups on GD 5. Randomization was stratified by body weight that produced similar group mean weights using PATH/TOX SYSTEM software (Xybion Medical Systems Corporation, Lawrenceville, NJ).

F_0_ females were quarantined for 12 days after receipt. Ten nonmated females received with the time-mated females were designated for disease monitoring 11 days after arrival; samples were collected for serological analyses, and the rats were euthanized, necropsied, and examined for the presence of disease or parasites. The health of the F_1_ rats was monitored during the study according to the protocols of the NTP Sentinel Animal Program (Appendix C). Pinworms (Syphacia spp.) were diagnosed in sentinel animals during routine health monitoring evaluations. Infected animals did not display clinical signs, and no pathological lesions were noted in relation to the presence of the pinworms. Following this finding, a successful plan of pinworm containment and eradication without the use of medication was developed and implemented in coordination with the testing laboratory. The testing laboratories were required to actively monitor animals to ensure the continued exclusion of pinworms from all studies going forward. All other test results were negative.

Beginning on GD 6, groups of 38 F_0_ time-mated female rats were administered BCE in 0.5% aqueous methylcellulose by gavage throughout gestation and lactation at one of three doses (75, 250, or 750 mg/kg/day) or the vehicle control only (0.5% aqueous methylcellulose). Formulations were administered daily, except for the day of delivery if the dam was in the process of delivering; dosing volumes were 5 mL/kg. Groups of 50 F_1_ female rats per dose group continued in the study after weaning and were administered 0.5% aqueous methylcellulose by gavage containing the same respective BCE doses for 2 years. Groups of 50 F_1_ male rats were not dosed after weaning but were assigned to groups corresponding to the doses their respective dams received during the perinatal phase.

F_0_ female rats were housed individually during gestation and with their respective litters during lactation. Feed and water were available ad libitum. F_0_ female body weights were recorded at arrival, on GD 5, and then daily throughout the rest of gestation and lactation. The day of parturition was considered to be lactation day (LD) 0. On apparent GD 25, all time-mated female rats that failed to deliver were euthanized, and the uteri were examined and stained for evidence of implantation. Total litter weight and litter weights by sex were collected on postnatal day (PND) 1. Individual F_1_ pup weights were recorded on PNDs 4, 7, 12, 15, 18, 21, 24, and 28. Clinical observations and survival were evaluated throughout lactation.

F_1_ litters were standardized on PND 4 to eight pups per litter, with at least two pups of each sex and a preference for four males and four females each. Litters that did not meet the minimum of eight pups (or had fewer than two pups of either sex) were removed from the study. On the day the last litter reached PND 26, pups (two/sex/litter) were randomly selected from 25 litters for each dose group and assigned to the 2-year study. On the day the last litter reached PND 28, dams were removed from the cages, and the pups were weaned. Weaning marked the beginning of the 2-year study.

After weaning, F_1_ rats were housed up to two (males) or up to five (females) per cage. Feed and water were available ad libitum. Cages were changed at least once weekly through PND 4, then changed at least twice weekly. Racks were changed and rotated at least every 2 weeks. Further details of animal maintenance are given in Table 1.

Table 1 Experimental Design and Materials and Methods in the Perinatal and Two-year Gavage Studies of Black Cohosh Root Extract

Rats | Mice
Study Laboratory
Battelle (Columbus, OH) | Same as rats
Strain and Species
Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) | B6C3F1/N
Animal Source
Envigo (formerly Harlan Laboratories, Inc., Indianapolis, IN) | Taconic Biosciences, Inc. (Germantown, NY)
Time Held Before Studies
F_0_ females: 4 days | 11 days
Average Age When Studies Began
F_0_ females: 12–15 weeks | 5–6 weeks
Date of First Dose
F_0_ females: May 18, 2012 | April 9, 2012
F_1_ females: July 2, 2012
F_1_ males: July 3, 2012 (not dosed postweaning, perinatal exposure only)
Duration of Dose
F_0_ females: GD 6 through LD 28 | Interim evaluations: 3 and 12 months
F_1_: Perinatal only (males) or perinatal plus 2 years (females) | 2-year study: 2 years
Date of Last Dose
F_0_ females: July 2, 2012 | 3-month interim evaluation: July 8, 2012
F_1_: June 30, 2014 (females) | 12-month interim evaluation: April 7, 2013
| 2-year study: April 10, 2014
Necropsy Dates
F_1_: June 30–July 3, 2014 | 3-month interim evaluation: July 9, 2012
| 12-month interim evaluation: April 8, 2013
| 2-year study: April 7–11, 2014
Average Age at Necropsy
F_1_: 2 years | 3-month interim evaluation: 3 months
| 12-month interim evaluation: 12 months
| 2-year study: 2 years
Size of Study Groups
F_0_ females: 38 | 3- and 12-month interim evaluations: 10 females each
F_1_ (2-year study): 50/sex | 2-year study: 50 females
Method of Distribution
Animals were distributed randomly into groups of approximately equal initial mean body weights | Same as rats
Animals per Cage
F_0_ females: 1 (with litter) | Cyclicity males: Up to 2
F_1_: Up to 2 (males) or up to 5 (females) | Females: Up to 4
Method of Animal Identification
F_0_ females: Cage card and tail marking with permanent pen | Cage card and tail tattoo
F_1_ (pups): Limb tattoo
F_1_ (2-year study): Cage card and tail tattoo
Diet
Irradiated NIH-07 wafer feed (perinatal phase) or irradiated NTP-2000 wafer feed (2-year study) (Zeigler Brothers, Inc., Gardners, PA), available ad libitum, changed twice weekly | Irradiated NTP-2000 wafer feed (Zeigler Brothers, Inc., Gardners, PA), available ad libitum, changed once weekly
Water
Tap water (Columbus, OH municipal supply) via automatic watering system (Edstrom Industries, Inc., Waterford, WI), available ad libitum | Same as rats
Cages
Solid polycarbonate (Lab Products, Inc., Seaford, DE), changed weekly through PND 4, then twice weekly, rotated every 2 weeks | Solid polycarbonate (Lab Products, Inc., Seaford, DE), changed weekly (males) or twice weekly (females), rotated every 2 weeks
Bedding
Irradiated Sani-Chips^®^ (P.J. Murphy Forest Products Corporation, Montville, NJ), changed with cage changes | Same as rats
Rack Filters
Spun-bonded polyester (Snow Filtration Company, Cincinnati, OH), changed every 2 weeks | Same as rats
Racks
Stainless steel (Lab Products, Inc., Seaford, DE), changed and rotated every 2 weeks | Same as rats
Animal Room Environment
Temperature: 71°F–74°F Relative humidity: 23%–78% Room fluorescent light: 12 hours/day Room air changes: at least 10/hour | Temperature: 69°F–80°F Relative humidity: 27%–69% Room fluorescent light: 12 hours/day Room air changes: at least 10/hour
Doses
F_0_ and F_1_ females: 0, 75, 250, and 750 mg/kg/day in 0.5% aqueous methylcellulose; 5 mL/kg dosing volume | 0, 30, 100, 300, and 1,000 mg/kg/day in 0.5% aqueous methylcellulose; 10 mL/kg dosing volume
Type and Frequency of Observation
F_0_ females: Observed twice daily. Weighed on GD 5 and then daily throughout the rest of gestation and lactation. | Observed twice daily. Weighed at randomization, day 1, weekly for the first 3 months, every 4 weeks thereafter, and at study termination. Clinical observations were recorded every 4 weeks and at study termination.
F_1_ rats: Observed twice daily. Litter data (litter count by sex, litter weights by sex, and litter observations) were recorded on PND 1. Pups were weighed on PNDs 4, 7, 12, 15, 18, 21, 24, and 28, weekly for the next 3 months, every 4 weeks thereafter, and at study termination. Clinical observations were recorded every 4 weeks, beginning on day 29, and at study termination.
Method of Euthanasia
Carbon dioxide | Same as rats
Necropsy
Necropsies were performed on all F_1_ rats. | Necropsies were performed on all female mice in the 2-year study. Spleen weights were collected at the 3-month and 12-month interim evaluations.
Histopathology
Complete histopathology was performed on all F_1_ rats. In addition to gross lesions and tissue masses, the following tissues were examined: adrenal glands, brain (olfactory bulbs, fronto-parietal cortex including basal ganglia, mid-parietal cortex and thalamus, mid-brain with substantia nigra and red nucleus, posterior colliculi, mid-cerebellum including cranial nerve VIII, and posterior medulla), clitoral glands, esophagus, eyes, femur (including diaphysis with marrow cavity and epiphysis [femoral condyle with epiphyseal cartilage plate, articular cartilage, and articular surface]), Harderian glands, heart and aorta, large intestine (cecum, colon, and rectum), small intestine (duodenum, jejunum, and ileum), kidneys, liver (two sections including left lateral lobe and median lobe) lungs and mainstem bronchi, lymph nodes (mandibular and mesenteric), mammary gland with adjacent (inguinal) skin, nasal cavity and nasal turbinates, ovaries, pancreas, parathyroid glands, pituitary gland, preputial glands, prostate gland, salivary glands, seminal vesicles, spleen, stomach (forestomach and glandular), testes with epididymides, thymus, thyroid gland, trachea, urinary bladder, uterus, and vagina with cervix. If neurological signs were present, the spinal cord and nerves (sciatic, tibial, and trigeminal with ganglion) were examined microscopically. If neuromuscular signs were present, the thigh muscle was examined microscopically. | 3- and 12-month interim evaluations: Histopathology was performed on the spleen and left femur (including bone marrow) only. 2-year study: Complete histopathology was performed on all female mice. In addition to gross lesions and tissue masses, the following tissues were examined: adrenal glands, brain (olfactory bulbs, fronto-parietal cortex including basal ganglia, mid-parietal cortex and thalamus, mid-brain with substantia nigra and red nucleus, posterior colliculi, mid-cerebellum including cranial nerve VIII, and posterior medulla), clitoral glands, esophagus, eyes, femur (including diaphysis with marrow cavity and epiphysis [femoral condyle with epiphyseal cartilage plate, articular cartilage, and articular surface]), gallbladder, Harderian glands, heart and aorta, large intestine (cecum, colon, and rectum), small intestine (duodenum, jejunum, and median lobe), kidney, liver, lungs and mainstem bronchi, lymph nodes (mandibular and mesenteric), mammary gland with adjacent (inguinal) skin, nasal cavity and nasal turbinates (3 sections), ovaries, pancreas, parathyroid glands, pituitary gland, salivary glands, spleen, stomach (forestomach and glandular), thymus, thyroid gland, trachea, urinary bladder, uterus, and vagina with cervix. If neurological signs were present, the spinal cord and nerves (sciatic and trigeminal with ganglion) were examined microscopically. If neuromuscular signs were present, the thigh muscle was examined microscopically.
Hematology
None | Following 3 months and 12 months of dose administration, blood was collected from the retroorbital sinus for hematology and micronuclei determinations.
| Hematology: erythrocyte count, hemoglobin, manual hematocrit, hematocrit, mean corpuscular volume, mean corpuscular hemoglobin, mean corpuscular hemoglobin concentration, leukocyte count and differential, reticulocyte count, platelet count, and qualitative evaluation of morphological features in all cellular components.
Bone Marrow Cell Count and Cytology
None | Following 3 months and 12 months of dose administration, bone marrow from the right femur was collected for total cell count per femur. Bone marrow from the sternum was collected for cytological evaluation (M:E ratio, morphology).

GD = gestation day; LD = lactation day; PND = postnatal day; M:E = myeloid:erythoid.

Two diets were utilized in the rat studies: (1) NIH-07 during the perinatal phase and (2) NTP-2000 during the postnatal phase. The NIH-07 diet is a higher protein diet that supports reproduction and lactation in rodents, whereas the NTP-2000 diet is a lower protein diet that decreases the incidence of chronic nephropathy in adult rats. Information on feed composition and contaminants for both diets is provided in Appendix B.

### Study Design for Mice

Female B6C3F1/N mice were approximately 3–4 weeks old upon receipt and were quarantined for 11 days before study start. Mice were randomly assigned to one of five dose groups (n = 70 female mice per dose group). Randomization was stratified by body weight that produced similar group mean weights using PATH/TOX SYSTEM software (Xybion Medical Systems Corporation, Lawrenceville, NJ).

Twenty male and 20 female mice were randomly selected for parasite evaluation and gross observation of disease. The health of the mice was monitored during the study according to the protocols of the NTP Sentinel Animal Program (Appendix C). All test results were negative.

Mice were administered BCE in 0.5% aqueous methylcellulose by gavage at one of four doses (30, 100, 300, or 1,000 mg/kg/day) or the vehicle control (0.5% aqueous methylcellulose). Formulations were administered daily for 2 years; dosing volumes were 10 mL/kg. Ten female mice per dose group were removed for each interim evaluation at 3 and 12 months.

Mice were housed up to two (cyclicity males) or up to four (females) per cage. Up to four male mice were maintained per rack to ensure cyclicity in female mice, but these male mice were not evaluated in the study. Feed and water were available ad libitum. Cages were changed at least once weekly (males) or twice weekly (females) and rotated every 2 weeks. Racks were changed and rotated every 2 weeks. Further details of animal maintenance are given in Table 1. Information on feed composition and contaminants is given in Appendix B.

### Clinical Examinations and Pathology

In the 2-year studies in rats and mice, animals were observed twice daily for signs of morbidity and moribundity and were weighed initially, weekly for the next 3 months, every 4 weeks thereafter, and at study termination. Clinical observations were recorded every 4 weeks and at study termination.

At the 3-month and 12-month mouse interim evaluations, blood was collected from the retroorbital sinus for hematology and micronuclei determinations. Mice were anesthetized with a carbon dioxide/oxygen mixture and bled in a random order. Blood was collected into tubes containing K_3_ EDTA (tripotassium ethylenediaminetetraacetic acid). Hematology parameters were analyzed using an Advia^®^ 120 system (Bayer Diagnostics Division, Tarrytown, NY). The parameters measured are listed in Table 1. Samples for erythrocyte micronuclei determination were stored at 2°C–8°C immediately after collection and shipped to Integrated Laboratory Systems, LLC (ILS, Durham, NC) for analysis. Full necropsy was not performed on these animals. Spleen weights were collected, and histopathology was performed on the spleen and left femur only. Bone marrow was collected from the right femur for determination of total cell count and from the sternum for cytological evaluation (myeloid:erythoid [M:E] ratio and morphological assessment). Bone marrow total cell counts were quantified per femur using an Advia 120 system (Bayer Diagnostics Division, Tarrytown, NY). Three slides were prepared from the sternum bone marrow sample using the paint brush technique. A 500-cell differential cell count was performed on the sternum bone marrow slides stained with Wright’s Giemsa stain to calculate the M:E ratio. Bone marrow cytological evaluation was performed by the study clinical pathologist.

Complete necropsies and microscopic examinations were performed on all F_1_ male and female rats and female mice that continued in the 2-year studies. At necropsy, all organs and tissues were examined for grossly visible lesions, and all major tissues were fixed and preserved in 10% neutral buffered formalin, except for eyes, testes (rats), vaginal tunics (rats), and epididymides (rats), which were first fixed in Davidson’s solution or modified Davidson’s solution. Tissues were processed and trimmed, embedded in paraffin, sectioned to a thickness of 4–6 μm, and stained with hematoxylin and eosin (H&E) for microscopic examination. For all paired organs (e.g., adrenal gland, kidney, ovary), samples from each organ were examined. The uterine horns were bisected at their midpoint, and one transverse section was taken from the midpoint of each horn for histopathology evaluation; the two free portions of each uterine horn, the uterine body, including the cervix, and the vagina were also examined. Tissues examined microscopically are listed in Table 1.

Microscopic evaluations were completed by the study laboratory pathologist, and the pathology data were entered into the Toxicology Data Management System. The report, slides, paraffin blocks, residual wet tissues, and pathology data were sent to the NTP Archives for inventory, slide/block match, wet tissue audit, and storage. The slides, individual animal data records, and pathology tables were evaluated by a quality assessment (QA) pathologist at a pathology laboratory independent of the study laboratory. The individual animal records and tables were compared for accuracy, the slide and tissue counts were verified, and the histotechnique was evaluated. For the 2-year studies, a QA pathologist evaluated slides from all neoplasms and all potential target organs, which included the bone marrow, kidney, thymus, and thyroid gland of male and female rats; the mammary gland, ovary, pituitary gland, spleen, uterus, and vagina of female rats; and the liver of male rats. For mice, the target organs included the spleen of female mice in the 3-month and 12-month interim evaluations and the adrenal gland, bone marrow, liver, ovary, skin, thymus, thyroid gland, uterus, and vagina of female mice in the 2-year study.

After a review of the laboratory reports and selected histopathology slides by a quality assessment (QA) pathologist, the findings and reviewed slides were submitted to a Pathology Working Group (PWG) coordinator for a second independent review. Any inconsistencies in the diagnoses made by the study laboratory and QA pathologists were resolved by the Division of Translational Toxicology (DTT) pathology peer-review process. Final diagnoses for reviewed lesions represent a consensus of the PWG or a consensus between the study laboratory pathologist, DTT pathologist, QA pathologist(s), and the PWG coordinator. Details of these review procedures have been described, in part, by Maronpot and Boorman^124^ and Boorman et al.^125^ For subsequent analyses of the pathology data, the decision of whether to evaluate the diagnosed lesions for each tissue type separately or combined generally was based on the guidelines of Brix et al.^126^

In addition to the routine pathology review, a step section analysis of the kidneys from the perinatal and 2-year rat study was performed. Paraffin-embedded kidneys from male and female rats were sectioned at 1 mm intervals to obtain three to four additional sections per kidney to allow for observation of additional renal tumors. The evaluation of these additional kidney slides was conducted by the QA pathologist. A PWG, separate from the PWG for the perinatal and 2-year rat study, evaluated representative slides from the kidney step section review. Final diagnosis of the kidney step section review represents a consensus between the QA pathologist, the DTT pathologist, and the kidney step PWG.

## Statistical Methods

For all analyses, p values ≤0.05 were considered statistically significant. Statistical significance is one component of the “weight of evidence” approach to evaluate carcinogenicity (described in the Explanation of Levels of Evidence of Carcinogenic Activity section).

### Survival Analyses

The probability of survival was estimated by the product-limit procedure of Kaplan and Meier^127^ and is presented graphically. Animals surviving to the end of the observation period are treated as censored observations, as are animals dying from unnatural causes within the observation period. Animals dying from natural causes are included in analyses and are treated as uncensored observations. For the 2-year mouse study, dose-related trends are identified with Tarone’s life-table test,^128^ and pairwise dose-related effects are assessed using Cox’s log-rank method.^129^ For the rat perinatal and 2-year study, dose-related trends and pairwise dose-related effects on survival are assessed using a Cox proportional hazards model^129^ with a random litter effect. All reported p values for the survival analyses are two-sided.

### Calculation of Incidence

The incidences of neoplasms or nonneoplastic lesions are presented as the numbers of animals bearing such lesions at a specific anatomical site. For calculation of incidence rates, the denominator for most neoplasms and all nonneoplastic lesions is the number of animals for which the site was examined microscopically. When macroscopic examination was required to detect neoplasms in certain tissues (e.g., mesentery, pleura, peripheral nerve, skeletal muscle, tongue, tooth, and Zymbal’s gland) before microscopic evaluation, however, the denominator consists of the number of animals that had a gross abnormality. When neoplasms had multiple potential sites of occurrence (e.g., leukemia or lymphoma), the denominator consists of the number of animals on which a necropsy was performed. Additional study data also give the survival-adjusted neoplasm rate for each group and each site-specific neoplasm. This survival-adjusted rate (based on the Poly-3 method described below) accounts for differential mortality by assigning a reduced risk of neoplasm, proportional to the third power of the fraction of time on study, only to site-specific, lesion-free animals that do not reach terminal euthanasia.

### Analysis of Neoplasm and Nonneoplastic Lesion Incidence

Statistical analyses of neoplasm and nonneoplastic lesion incidence considered two features of the data. Some animals did not survive the entire 2 years of the study, so survival differences between groups had to be considered. In addition, for the rat perinatal and 2-year study, up to two animals per sex were randomly selected from each litter to participate in the study. The statistical analysis of lesion incidence used the Poly-3 test to account for survival differences, with a Rao-Scott adjustment for litter effects, as described below.

The Poly-k test^130-132^ was used to assess neoplasm and nonneoplastic lesion prevalence. This test is a survival-adjusted quantal-response procedure that modifies the Cochran-Armitage linear trend test to account for survival differences. More specifically, this method modifies the denominator in the quantal estimate of lesion incidence to approximate more closely the total number of animal years at risk. For analysis of a given site, each animal is assigned a risk weight. This value is 1 if the animal had a lesion at that site or if it survived until terminal euthanasia; if the animal died before terminal euthanasia and did not have a lesion at that site, its risk weight is the fraction of the entire study time that it survived, raised to the kth power.

This method yields a lesion prevalence rate that depends only on the choice of a shape parameter for a Weibull hazard function describing cumulative lesion incidence over time.^130^ Unless otherwise specified, a value of k = 3 was used in the analysis of site-specific lesions. This value was recommended by Bailer and Portier^130^ after an evaluation of neoplasm onset time distributions for a variety of site-specific neoplasms in control Fischer 344 rats and B6C3F1 mice.^133^ Bailer and Portier^130^ showed that the Poly-3 test gave valid results if the true value of k was anywhere in the range from 1 to 5. A further advantage of the Poly-3 method is that it does not require lesion lethality assumptions. Variation introduced by the use of risk weights, which reflect differential mortality, was accommodated by adjusting the variance of the Poly-3 statistic as recommended by Bieler and Williams.^134^ Poly-3 tests used the continuity correction described by Nam.^135^

Littermates tend to be more like each other than like fetuses/pups in other litters. Failure to account for correlation within litters leads to underestimates of variance in statistical tests, resulting in higher probabilities of Type I errors (“false positives”). Because up to two pups/sex/litter were present in the rat perinatal and 2-year study, the Poly-3 test was modified to accommodate litter effects using the Rao-Scott approach.^136^ The Rao-Scott approach accounts for litter effects by estimating the ratio of the variance in the presence of litter effects to the variance in the absence of litter effects. This ratio is then used to adjust the sample size downward to yield the estimated variance in the presence of litter effects. The Rao-Scott approach was implemented in the Poly-3 test as recommended by Fung et al.^137^ formula ₸_RS2_.

Tests of significance included pairwise comparisons of each dosed group with control groups and a test for an overall dose-related trend. Continuity-corrected Rao-Scott-adjusted Poly-3 tests were used in the analysis of rat lesion incidence and reported p values are one sided. The significance of a lower incidence or negative trend in lesions is approximated as 1−p with the letter N added (e.g., p = 0.99 is presented as p = 0.01N). For the mouse study in which neoplasms and nonneoplastic lesions were observed without litter structure, Poly-3 tests that included the continuity correction, but without adjustment for potential litter effects, were used for trend and pairwise comparisons to the control group.

To evaluate incidence rates by litter in the rat perinatal and 2-year study, the proportions of litters affected by each lesion type were tested among groups. Cochran-Armitage trend tests and Fisher’s exact test^138^ were used to test for trends and pairwise differences from the control group, respectively.

### Analysis of Continuous Variables

Before statistical analysis, outliers identified using the Dixon and Massey test^139^ for small samples (n < 20) and Tukey’s outer fences method^140^ for large samples (n ≥ 20) were examined by DTT personnel, and biologically implausible values (likely due to experimental error) were eliminated from the analysis. Organ and body weight measurements, which historically have approximately normal distributions, were analyzed with the parametric multiple comparison procedures of Dunnett^141^ and Williams.^142,143^ Litter sizes, pup survival, gestation lengths, hematology endpoints, and proportions of male pups per litter for all studies were analyzed using the nonparametric multiple comparison methods of Shirley^144^ [as modified by Williams^145^] and Dunn,^146^ given that these endpoints typically have skewed distributions. For all quantitative endpoints unaffected by litter structure, the Jonckheere test^147^ was used to assess the significance of the dose-related trends and to determine at the 0.01 level of significance, whether a trend-sensitive test (the Williams or Shirley test) was more appropriate for pairwise comparisons than a test that does not assume a monotonic dose-related trend (the Dunnett or Dunn test).

Postweaning body weights were measured on two pups/sex/litter in the rat perinatal and 2-year study; more than two pups/sex/litter were possible in preweaning body weight measurements. The analyses of pup body weights and pup body weights adjusted for litter size (described below) took litter effects into account using a mixed model with litter as a random effect. To adjust for multiple comparisons, a Dunnett-Hsu adjustment was used.^148^ Dam body weights during gestation and lactation were analyzed with the parametric multiple comparison procedures of Dunnett^141^ or Williams,^142,143^ depending on whether the Jonckheere test indicated the use of a trend-sensitive test. P values for these analyses are two-sided.

### Analysis of Gestational and Fertility Indices

Cochran-Armitage trend tests were used to test the significance of trends in gestational and fertility indices across dose groups in the rat perinatal and 2-year study. Fisher’s exact test was used to conduct pairwise comparisons of each dosed group with the control group. P values for these analyses are two-sided.

### Body Weight Adjustments

Preweaning pup body weights in the rat perinatal and 2-year study were adjusted for live litter size as follows. A linear model was fit to body weights as a function of dose and litter size. The estimated coefficient of litter size was then used to adjust each pup body weight according to the difference between its litter size and the mean litter size. Prestandardization PND 4 body weights were adjusted for PND 1 litter size, and body weights measured between PND 4 poststandardization and PND 28 were adjusted for PND 4 poststandardization litter size. After adjustment, body weights were analyzed with a linear mixed model with a random litter effect.

### Historical Control Data

The concurrent control group is the most valid comparison to the dosed groups and is the only control group analyzed statistically in NTP bioassays. Historical control data are often helpful in interpreting potential dose-related effects, however, particularly for uncommon or rare neoplasm types. For meaningful comparisons, the conditions for studies in the historical control data must be generally similar. Significant factors affecting the background incidence of neoplasms at a variety of sites are diet, sex, strain/stock, and route of exposure. The NTP historical control database contains all 2-year studies for each species, sex, and strain/stock with histopathology findings in control animals completed within the most recent 5-year period,^149-151^ including the concurrent control for comparison across multiple technical reports. In general, the historical control data for a given study includes studies using the same route of administration, and the overall incidence of neoplasms in controls for all routes of administration is included for comparison, including the current study. In the historical control data set, only one comparator for same mode of administration (trans-resveratrol) was available for methylcellulose gavage in rats.

## Quality Assurance Methods

The 2-year studies were conducted in compliance with U.S. Food and Drug Administration Good Laboratory Practice Regulations.^152^ In addition, the 2-year study reports were audited retrospectively by an independent QA contractor against study records submitted to the NTP Archives. Separate audits covered completeness and accuracy of the pathology data, pathology specimens, final pathology tables, and a draft of this NTP Technical Report. Audit procedures and findings are presented in the reports and are on file at NIEHS. The audit findings were reviewed and assessed by DTT staff, and all comments were resolved or otherwise addressed during the preparation of this Technical Report.

## Genetic Toxicology

The genetic toxicity of BCE was assessed by testing whether the chemical induces mutations in various strains of Salmonella typhimurium and Escherichia coli or increases the frequency of micronucleated erythrocytes in mouse peripheral blood. The protocol for these studies and the results are given in Appendix D.

The genetic toxicity studies have evolved from an earlier effort to develop a comprehensive database permitting a critical anticipation of a chemical’s carcinogenicity in experimental animals based on numerous considerations, including the relationship between the molecular structure of the chemical and its observed effects in short-term in vitro and in vivo genetic toxicity tests (structure-activity relationships). The short-term tests were developed originally to clarify proposed mechanisms of chemical-induced DNA damage, given the relationship between electrophilicity and mutagenicity,^153^ and the somatic mutation theory of cancer.^154,155^ Not all cancers, however, arise through genotoxic mechanisms.

### Bacterial Mutagenicity

DNA reactivity combined with Salmonella mutagenicity is highly correlated with induction of carcinogenicity in multiple species/sexes of rodents and at multiple tissue sites.^156^ A positive response in the Salmonella test was shown to be the most predictive in vitro indicator for rodent carcinogenicity (89% of the Salmonella mutagens are rodent carcinogens).^157,158^ Additionally, no battery of tests that included the Salmonella test improved predictivity over the Salmonella test alone. Other tests, however, can provide useful information on the types of DNA and chromosomal damage induced by the chemical under investigation.

### Peripheral Blood Micronucleus Test

Micronuclei (literally “small nuclei” or Howell-Jolly bodies) are biomarkers of induced structural or numerical chromosomal alterations and are formed when acentric fragments or whole chromosomes fail to incorporate into either of two daughter nuclei during cell division.^159,160^ Acute in vivo bone marrow chromosome aberration and micronucleus tests appear to be less predictive of carcinogenicity than the Salmonella test.^161,162^ However, clearly positive results in long-term peripheral blood micronucleus tests have high predictivity for rodent carcinogenicity; a weak response in one sex only or negative results in both sexes in this assay do not correlate well with either negative or positive results in rodent carcinogenicity studies.^163^ Because of the theoretical and observed associations between induced genetic damage and adverse effects in somatic and germ cells, determination of in vivo genetic effects is important to overall understanding of risks associated with exposure to a particular chemical.