# Introduction

Figure 1

Black Cohosh (CASRN 84776-26-1)

Synonyms: Actaea racemosa L, Cimicifuga racemosa L., black snakeroot, macrotys, rattleweed, rattleroot, snake root, wanzenkraut, bugbane, baneberry.

Image courtesy of King’s American Dispensatory.^3^

## Chemical and Physical Properties

Black cohosh (Actaea racemosa L.) is a perennial plant of the buttercup family native to eastern North America. It is erect and smooth-stemmed and ranges from 4 to 8 feet tall with long, wand-like, white flowers in midsummer.^4^ Preparations of black cohosh include the fresh or dried roots and rhizomes of A. racemosa L.^5,6^ Its roots are straight, dark brown, and odorless. When cut, the interior of the roots has the appearance of off-white, porous wood. The plant’s rhizomes are harvested in autumn and can be used fresh in tinctures or dried in decoctions, liquid extracts, and tinctures.^7,8^

Only a small proportion (<10%) of the constituents in black cohosh extract is known.^9,10^ Extracts of black cohosh rhizomes contain various triterpene glycosides, phenolic acids (e.g., isoferulic acid and fukinolic acid), flavonoids, alkaloids, volatile oils, and tannins.^11,12^ Although the constituents responsible for the pharmacological or toxicological effects of black cohosh have not been identified, various components have exhibited biological activity. For example, triterpene glycosides were shown to inhibit breast cancer cell proliferation,^13^ and phenolic acids extracted from black cohosh were shown to prevent menadione-induced DNA damage in breast cancer cells.^14^

## Production, Use, and Human Exposure

Black cohosh roots and rhizomes have been used for centuries by eastern North American indigenous groups for enhancing female health, treating abnormal or painful menstruation, relieving pregnancy-related pain or distress, and promoting uncomplicated delivery and quick recovery.^4,15,16^ Black cohosh also has been used to address other maladies, such as kidney problems, rheumatism, colds, aches, and coughs.^8,17^ Black cohosh was introduced in Europe in the late 19th century. In recent years, its popularity for the treatment of menopause has grown in part from a desire to shift away from hormone-replacement therapies that can produce unwanted side effects.^9^ Of women who discontinue hormone therapy and use herbal remedies, an estimated 30% choose black cohosh products.^18^

Black cohosh products are widely available and primarily marketed to alleviate symptoms of menopause, premenstrual syndrome (PMS), and menstrual pain. In 2002, the World Health Organization summarized the evidence for medicinal uses of black cohosh, highlighting that clinical data supported its use in the “treatment of climacteric symptoms such as hot flushes, profuse sweating, sleeping disorders and nervous irritability.”^19^ Although black cohosh typically is used during menopause, it has been recommended by 20%–30% of midwives in the United States to induce labor in pregnant women or for other purposes.^20-23^

In 2019, black cohosh was the 15th top-selling botanical dietary supplement in the United States.^24^ Black cohosh dietary supplements are sold as powdered whole herb, liquid extracts, or dried extracts in pill form and can be found alone or in combinations with other botanicals.^25^ Extraction and preparation methods may vary by manufacturer and are often proprietary. Commercial pharmaceutical formulations of black cohosh include Remifemin^®^ (sold in Germany since 1956) and Remixin. Black cohosh is typically found in combination products marketed for improving female health, such as general wellness supplements for use during menopause, phytoestrogen supplements, sleep aids for women, and female-specific vitamins.^25^

Black cohosh products generally are standardized to the content of triterpene glycosides, such as 23-epi-26-deoxyactein (27-deoxyactein), actein, or cimicifugosides.^26,27^ Standardizing to attain a triterpene content of 2.5%, or approximately 1 mg of a given triterpene, is common.^28,29^ Remifemin^®^ has been widely studied for efficacy and is standardized to 20 mg of black cohosh root and rhizome per tablet^30^; however, the chemical makeup of black cohosh products varies widely.^31,32^ One study analyzed triterpene glycoside content in 11 black cohosh products and found amounts ranging from 0.36% to 7.55%; 8 of the 11 products had label claims of 2.5% triterpene glycoside content.^31^

Black cohosh doses in clinical trials evaluating efficacy have ranged from 6.5 to 160 mg/day for 1–12 months.^10,33^ The expert committee on herbal remedies established by the German Federal Institute for Drugs and Medical Devices to independently evaluate the safety and efficacy of phytomedicines, Commission E, recommends 40 mg/day of alcohol extracts of black cohosh, not to exceed 6 months of use.^6^ The manufacturer of Remifemin^®^ recommends a dose equivalent to approximately 5 mg/day, taken as two tablets containing 2.5 mg black cohosh root/rhizome per day.^34^ Botanical supplements that contain a mixture of active ingredients, such as black cohosh, further complicate the exposure profile and safety evaluation.^35^ Data on internal concentrations of chemical constituents or metabolites of black cohosh after oral intake are limited. Black cohosh products are also marketed in combination with other botanicals, such as red clover, soy isoflavones, St. John’s wort, chasteberry, and dong quai.^36,37^

## Regulatory Status

In the United States, black cohosh products are sold as dietary supplements and are therefore regulated under the Dietary Supplement Health and Education Act.^38^ For dietary supplements on the market before October 15, 1994, there is no requirement for proof of safety to remain on the market. The labeling requirements for supplements allow warnings and dosage recommendations as well as substantiated “structure or function” claims. All claims must prominently note they have not been evaluated by the U.S. Food and Drug Administration and bear the statement, “This product is not intended to diagnose, treat, cure, or prevent any disease.”^39^ Thus, dietary supplements containing black cohosh cannot claim to treat PMS or menopausal symptoms.

In Europe, there is general support for the use of black cohosh for gynecological symptoms. Commission E recommended black cohosh for treating PMS, menstrual cramps, and menopausal symptoms for a duration of 6 months or less.^6^ The European Medicines Agency’s Herbal Medicinal Products Committee released a monograph on Cimicifuga racemosa (L.) Nutt., rhizoma, indicating black cohosh for relief of menopausal symptoms such as hot flashes and profuse sweating.^40^

## Absorption, Distribution, Metabolism, and Excretion

### Experimental Animals

The literature contains few studies on the metabolism of black cohosh in rodents. Expression of phase I and II enzymes and transporters in the liver, kidney, and small intestine were evaluated in female C57BL/6J wild type mice following gavage administration of up to 500 mg/kg body weight (mg/kg) of an extract of black cohosh for 28 days.^41^ Dose- and time-dependent, liver-specific up-regulation of Cyp3a11 was observed, with a sevenfold increase in the 500 mg/kg group compared to control animals after 14 days. The authors demonstrated that the mouse pregnane X receptor (PXR) played a direct role in the induction of Cyp3a11 by using a combination of in vivo (Pxr-null, PXR-humanized [hPXR], and double transgenic CYP3A4/hPXR mice) and cell-based assays, whereas human PXR was not activated by the extract. Following a single gavage administration of 35.7 mg/kg actein (a constituent of black cohosh) to female Sprague Dawley rats, the maximum serum concentration (C_max_) was 2.4 μg/mL at 6 hours.^42^ Actein was detected in urine at 24 hours with a reported concentration of 777.07 ng/mL.

### Humans

The pharmacokinetics of 23-epi-26-deoxyactein were evaluated in menopausal women following single oral administration of black cohosh capsules (32 mg, 64 mg, or 128 mg extracted with 75% ethanol) containing 1.4 mg, 2.8 mg, or 5.6 mg of 23-epi-26-deoxyactein.^43^ Absorption was rapid, with C_max_ reached in ≤3 hours. Area under the concentration-time curve (AUC) and C_max_ (2.2–12.4 ng/L) increased proportionally to the dose. There was no dose-dependent difference in the serum elimination half-life (2.1–3.0 hours). The dose recovered in urine during the first 24 hours after administration was <0.01%. No metabolites were detected in urine or serum despite low concentrations of the parent compound observed in serum and urine. Metabolites also were not detected following incubation of 23-epi-26-deoxyactein with human hepatocytes. Incubation of 23-epi-26-deoxyactein with simulated human gastric fluid showed that it degraded over time, with an estimated half-life of 80.6 minutes. This finding suggests 23-epi-26-deoxyactein likely undergoes degradation in the stomach following oral administration, which leads to low systemic levels, as found in the pharmacokinetic study.

The literature generally shows limited effects of black cohosh on drug metabolism and disposition in humans. In human liver microsomes, seven tested black cohosh supplements (methanolic extracts) produced slight, but insignificant, activation or inhibition of CYP3A4.^44^ This observation is consistent with the finding that black cohosh supplement consumption (40 mg twice daily for 14 days) did not have a significant effect on CYP3A activity.^45^ Other studies using human liver microsomes have found that black cohosh (methanolic extract containing ≥5% total triterpene glycosides) inhibits UGT1A4, β-D-glucuronide formation, and 3-O-glucuronidation of estradiol.^46,47^

The pharmacokinetics of digoxin, a P-glycoprotein (P-gp) substrate, were not influenced following administration of 20 mg (twice daily for 14 days) of black cohosh extract (2.5% triterpene glycosides), suggesting that black cohosh constituents do not modulate P-gp activity.^48^ Similarly, 40 mg (twice daily for 14 days) of a black cohosh supplement (2.5% triterpene glycosides) did not modulate CYP2D6 in humans when debrisoquine was the substrate.^49^ A significant, but not clinically relevant, inhibition of CYP2D6 was reported, however, following administration of a supplement containing 1,090 mg (twice daily for 28 days) of black cohosh (0.2% triterpene glycosides).^50^

Potential herb-drug interactions of black cohosh have been demonstrated in some in vitro studies. Several studies reported inhibition of hepatic cytochrome P450 enzymes^44,51-54^ and UDP-glucuronosyltransferases^46,47^ by black cohosh. Sevior et al.^53^ reported inhibition of CYP2B6, CYP2C19, CYP(D)2C19, and CYP2E1, but not CYP2D6 and CYP3A4, enzymes by a methanolic black cohosh extract with median inhibitory concentration (IC_50_) values of 49.2, 36.3, 23.9, and 11.5 μg/mL, respectively. Studies have also shown inhibition of CYP1A2, CYP2D6, CYP2C9, and CYP3A4.^51,52^ The active inhibitory constituents, triterpene glycosides, fukinolic acid, and cimicifugic acids A and B, were identified by bioassay-directed fractionation. Although the triterpene glycosides (cimiracemoside A, 23-epi-26-deoxyactein, and actein) were weakly active for CYP2C9 and CYP3A4 (IC_50_: 25–100 μM), fukinolic acid and cimicifugic acids A and B strongly inhibited all CYP isozymes (IC_50_: 1.8–12.6 μM).

## Toxicity

### Experimental Animals

In a 13-week repeat-dose study conducted as part of the National Toxicology Program (NTP) research program on black cohosh, female Wistar Han rats and female B6C3F1/N mice were administered up to 1,000 mg/kg body weight/day (mg/kg/day) of an ethanolic extract of black cohosh via gavage.^55^ In both species, dosing did not affect mean body weights but did result in higher liver weights in the 500 and 1,000 mg/kg/day groups. Mild liver necrosis was noted in two rats in the 1,000 mg/kg/day group, but no significant microscopic findings were noted in mouse livers. Differences in kidney, pituitary gland, and ovary weights were reported but did not have microscopic correlates. Mean thymus weights of rats administered ≥500 mg/kg/day were lower than that of control animals and correlated with increased incidences of apoptosis in the thymus; this histological finding was not observed in mice. Notably, increased frequencies of micronucleated peripheral red blood cells were observed in both species. Dose-dependent hematological changes were also found, consistent with a nonregenerative macrocytic decrease in the erythron that presented more severely in mice than in rats. Additionally, rare-to-occasional poikilocytes (including acanthocytes and schistocytes) and basophilic stippling were observed on the mouse peripheral blood smears. This combination of hematological changes was consistent with a condition known as megaloblastic anemia. Further investigation in female B6C3F1/N mice showed these hematological changes were consistent with functional cobalamin (and potentially folate) deficiencies, which are both known causes of megaloblastic anemia.^2^

Other in vivo studies have investigated hepatotoxicity with mixed findings. Marked changes in hepatic mitochondrial morphology were observed in female Wistar rats administered ≥100 mg/kg/day via gavage for 21 days; microvesicular steatosis developed in the 1,000 mg/kg/day group by study termination.^56^ On the other hand, male Wistar rats administered 300 mg/kg/day of a black cohosh extract for 30 days via gavage exhibited no changes in serum AST (aspartate transaminase), ALT (alanine transaminase), GGT (gamma-glutamyltransferase), ALP (alkaline phosphatase), or total or direct bilirubin and had normal liver histopathology.^57^ Reductions in hepatic GSH (glutathione) were observed.

### Humans

Acute complaints associated with black cohosh consumption have included headaches and gastrointestinal symptoms such as nausea, vomiting, and gastric discomfort (reviewed in Huntley^58^). One case of severe hyponatremia was reported when black cohosh was used to induce labor.^59^ Another possible concern is liver toxicity, as suggested by case reports of patients developing hepatitis or fulminant hepatic failure.^60-62^ In 2008, an expert committee convened by the United States Pharmacopeia evaluated 30 reports of black cohosh products and liver damage and found insufficient evidence to support a causal relationship.^63^ The committee nevertheless recommended including a warning label for hepatotoxicity on black cohosh products. Further analysis of data from 11 published case reports and 58 spontaneous reports did not support black cohosh hepatotoxicity.^64^ A meta-analysis of five clinical trials evaluating the efficiency of Remifemin^®^ also did not find black cohosh to be associated with abnormal liver function.^65^

A key problem in evaluating the available data on possible hepatotoxicity is the limited information on the type, amount, and quality of black cohosh products used and incomplete and/or unclear descriptions of the clinical presentation.^64^ Multiple sources of variation also exist in the production of botanical dietary supplements,^66^ including differences in preparation methods and potential adulteration with other types of cohoshes or toxicants. This variability may help to explain the heterogeneity of clinical reports, both in terms of clinical efficacy and toxicity. Overall, the consensus evidence for black cohosh-induced hepatotoxicity is weak, and more systematic investigation of this adverse effect is warranted.

## Reproductive and Developmental Toxicity

### Experimental Animals

Despite the predominant use of black cohosh by women, some of child-bearing age, minimal information is available regarding its reproductive and developmental effects. The literature contains no reproductive toxicity studies in animals. Regarding developmental effects, the previously described subchronic NTP studies found delayed onset of puberty in female Wistar Han rats and B6C3F1/N mice.^55^

Given the use of black cohosh for gynecological symptoms, the estrogenic activity of black cohosh and its constituents has been studied extensively.^29,67^ Findings in molecular studies evaluating the ability of components found in black cohosh to bind to estrogen receptors (ERs) are conflicting. Extracts of black cohosh were found to bind to ERs in rat, porcine, and human uterine cytosol preparations^68-70^ but not when incubated with recombinant ERα and ERβ receptors.^69,71,72^ In vivo studies in rodents have reported negative findings in uterotrophic assays,^55,73,74^ although some found decreased luteinizing hormone concentrations in ovariectomized rats.^70,75^ Findings in ovariectomized Sprague Dawley rats with black cohosh-supplemented diets showed an estrogenic effect in bone (particularly osteoblasts), which reduced serum and urinary biomarkers indicative of bone turnover or loss and preserved bone mineral density.^74,76^ Black cohosh may also exert estrogenic activity in the brain. A proposed mechanism for the regulation of hot flashes is the binding of black cohosh components to serotonin receptors found in the thermoregulatory region of the brain, rather than activation of ERs.^77^

### Humans

The literature contains few studies on adverse effects of black cohosh on female reproductive health. The available evidence generally suggests minimal effects.

In vitro, black cohosh extracts did not stimulate proliferation in human breast cancer MCF-7 cells, which would be expected of an ER agonist, but rather inhibited growth through induction of apoptosis.^13,78,79^ Proliferation of human prostate cancer cells also was inhibited by black cohosh extracts, possibly through activation of aryl hydrocarbon receptors.^80^ Exposure to an isopropanolic extract of black cohosh increased osteoprotegerin gene expression and protein secretion in human osteoblastic cells, suggesting an estrogenic effect in the bone.^81^

In line with findings from animal studies, a review of clinical studies did not find indications of estrogenic activity in the mammary gland or the endometrium.^82^ There was no increase in endometrial proliferation in a study of postmenopausal women given 40 mg of black cohosh daily for 1 year.^83^ No change in vaginal cytology or menstrual cyclicity was observed in women consuming 160 mg/day for up to 1 year.^84^ Black cohosh supplementation also did not modify reproductive hormones such as estradiol, follicle stimulating hormone, prolactin, or luteinizing hormone.^28,84-89^ In contrast, some studies have shown a decrease in luteinizing hormone or increased proliferation of the vaginal epithelium among women taking black cohosh products.^70,90^ These discrepancies could result from the complexity of the biological effect and variation in the chemical makeup of black cohosh products.

## Immunotoxicity

Immune modulation has been observed with black cohosh and some of its constituents. Studies using extracts of black cohosh found decreased cytokines in human peripheral whole blood^91^ and macrophages,^92^ inhibition of histamine release in rat peritoneal mast cells,^93^ and reduced nitric oxide production in murine macrophages.^94^ Immunological evaluations conducted as part of the NTP black cohosh research program showed increased liver weight and decreased spleen cell populations in female B6C3F1/N mice administered 1,000 mg/kg/day of the same black cohosh extract lot used in the present studies for 28 days.^95^ In that study, minimal changes in thymus cell populations and bone marrow cellularity were observed. Importantly, apart from an enhanced cytotoxic T lymphocyte response, no changes in the function of innate, cell-mediated, or humoral immunity were detected.^95^

Studies on ferulic and isoferulic acid, constituents found in extracts of black cohosh, suggested they could be responsible for some of the anti-inflammatory effects of black cohosh products. Ferulic acid and/or isoferulic acid decreased cytokine production in murine macrophages and in female ICR mice,^96^ inhibited COX-2 expression in lipopolysaccharide-induced macrophages,^97^ and reduced inflammation in rats.^98^ Other constituents of black cohosh—actein, cimigenol, and cimicifugoside—have been found to be immunosuppressive.^99,100^ In vitro assays of rhizome extracts from other species of the Cimicifuga genus found anticomplement activity in human serum^101^ and suppression of concanavalin A-stimulated BALB/c mice spleen cell proliferation,^102^ lymphocyte proliferation in mixed BALB/c and C57BL/6 mouse spleen cells,^103^ and C57BL/6 mouse T cell differentiation.^104^

## Carcinogenicity

### Experimental Animals

Given that black cohosh might be estrogenic and because of its prevalent use as a supplement among women, much of the available literature evaluates the relationship of black cohosh product use with breast cancer. However, over time, experimental studies using breast and endometrial cancer cell lines have shown that black cohosh is likely not estrogenic and either inhibits or has no effect on cancer cell growth.^40,58,67^

In vivo animal studies have shown a similar pattern in which black cohosh either inhibits or does not promote breast or uterine cancer growth. One study reported a decrease in the incidence of mammary fibroadenomas in female Sprague Dawley rats administered up to 35.7 mg/kg of black cohosh (n-butanolic extract) via oral intubation 6 days per week for 40 weeks.^105^ Consumption of 40 mg/day of an isopropanolic extract of black cohosh in the diet for up to 14 months did not promote or inhibit growth of mammary tumors in MMTV-neu mice (transgenic mice that spontaneously develop mammary tumors).^106^ In this study, however, increased pulmonary metastases were observed in animals consuming black cohosh. Endometrial adenocarcinoma cells implanted in ovariectomized rats did not respond negatively or positively to black cohosh consumption (60 mg of an isopropanolic extract of black cohosh per kg body weight via drinking water prepared daily for 5 weeks).^107^

The role of black cohosh in other cancers is less studied. Extract of black cohosh inhibited tumor development in immunodeficient nu/nu mice inoculated with LNCaP cells.^108^ Overall, there is little evidence that black cohosh promotes cancer growth, but further research is needed to evaluate its role in carcinogenesis in various tissues.

### Humans

The available human data do not support an association between black cohosh use and increased risk of breast cancer.^67,109,110^ The risk of developing other cancers with consumption of black cohosh has not been evaluated in human population studies. In relation to other types of cancer, extracts of black cohosh inhibited proliferation of HepG2 human liver cancer cells,^111^ HT29 human colon cancer cells,^112^ and LNCaP human prostate cancer cells.^80,113^

## Genetic Toxicity

A published NTP study reported that an ethanolic black cohosh extract (the same lot used in the present studies) produced significant, dose-dependent increases in micronucleated reticulocytes and micronucleated erythrocytes in the peripheral blood of female B6C3F1/N mice at doses ranging from 62.5 to 1,000 mg/kg/day via gavage for 13 weeks.^55^ Significant increases in micronucleated reticulocytes also were observed in the peripheral blood of female Wistar Han rats administered doses ranging from 15 to 1,000 mg/kg/day for 13 weeks via gavage.^55^ In a subsequent NTP study, a significant increase in micronuclei (reported as Howell-Jolly bodies) was observed in peripheral blood from female B6C3F1/N mice administered 1,000 mg/kg/day for 13 weeks by gavage.^2^

To evaluate whether the genotoxicity of black cohosh was specific to the lot used for the NTP animal studies, the same lot, as well as 14 other black cohosh products (including a standard reference material [XRM, ChromaDex, Inc.] for black cohosh extract), were tested in an in vitro flow-cytometric micronucleus assay using human B-lymphoblastoid TK6 cells.^114^ The lot used in the previous and present NTP studies produced significant, dose-dependent increases in micronuclei in TK6 cells when tested over a range of 30–500 µg/mL for 4 hours or 10–125 µg/mL for 24 hours. It did not induce micronuclei in the presence of 10% induced rat liver S9 mix, suggesting the active compound (or compounds) may have been detoxified. Samples from all 15 black cohosh sources induced significant increases in micronuclei in the absence of S9 mix when cells were first conditioned in culture medium containing a more physiologically relevant concentration of folic acid. Furthermore, use of the MultiFlow^®^ DNA Damage Assay indicated that induction of micronuclei in TK6 cells by the lot used in the present studies and the XRM standard reference material was due to an aneugenic (whole chromosome loss) versus a clastogenic (chromosome breakage) mode of action, an observation that was repeated in a subsequent study, also with TK6 cells.^115^ These same two samples shared characteristics with chemicals known to destabilize microtubules, as shown in a MultiFlow Aneugen Molecular Mechanism Assay, which uses TK6 cells to categorize chemicals with aneugenic activity as tubulin destabilizers, tubulin stabilizers, or Aurora kinase inhibitors.^115^ The observation that black cohosh extract—the same lot that was used for NTP animal studies—induces micronuclei in TK6 cells was repeated in another laboratory.^116^

TK6 cells exposed to 25–250 µg/mL of black cohosh extract from the same lot as that used for NTP animal studies were assessed for DNA damage at 0.5, 1, 2, 4, and 24 hours after exposure using the comet assay.^116^ DNA damage (% tail DNA) was significantly increased at the 0.5-, 1-, 2-, and 4-hour time points when cells were exposed to 250 μg/mL of black cohosh extract. The level of test article-induced DNA damage was highest at the 0.5-hour time point and decreased over time. DNA damage was not detected, however, in human hepatoblastoma HepG2 cells exposed to 50–500 µg/mL of this lot of black cohosh extract over the same time course using the comet assay.^116^ In the same study, phosphorylation of H2AX (γH2AX), a biomarker for double-strand DNA breaks, was observed in TK6 cells after 4 hours and 24 hours of exposure, accompanied by phosphorylation of cell cycle checkpoint proteins Chk1 and Chk2 at both time points and increases in p53 and p21 after 24 hours exposure.

The same lot of black cohosh extract was tested in Salmonella typhimurium strains TA100 and TA98 and Escherichia coli strain WP2 uvrA (pKM101) at doses ranging from 100 to 10,000 µg/plate, with or without 10% induced rat liver S9 mix.^114,117^ The result was judged to be equivocal in TA98 in the presence of S9 mix and otherwise negative in these tests. The same three tester strains were used to assay five additional black cohosh products from different lots or sources at doses ranging from 187.5 to 6,000 µg/plate, with or without 10% induced rat liver S9 mix, and judged all results to be negative.

In summary, black cohosh extract was genotoxic in rats and mice, and studies with human cells showed that a variety of extracts from different suppliers were genotoxic, indicating general genotoxic activity. Furthermore, studies with human cells showed that micronuclei were induced by an aneugenic mode of action, likely due to destabilization of microtubules.^114,115^ The same black cohosh lot as used in the present studies might also be capable of directly causing DNA damage, as indicated by the comet assay and activation of the DNA damage response,^116^ although clastogenic activity was not identified as a mode of action in TK6 cells exposed to similar black cohosh extract concentrations.^114,115^ Black cohosh does not appear to cause gene mutations, as assessed in bacterial mutagenicity assays.

## Study Rationale

In the NTP 3-month repeat-dose studies, black cohosh root extract (BCE) administration increased frequencies of micronucleated peripheral erythrocytes in both female rats and mice.^55^ Given the correlation of positive micronucleus assays and carcinogenicity^118^ and the lack of publicly available data to evaluate cancer risk, it was determined that a carcinogenicity study on black cohosh was warranted. These studies were conducted using the same lot of BCE used in previous NTP animal studies that showed increases in micronucleated peripheral erythrocytes.^55^ Perinatal exposure was included in the rat study to reflect the potential use of black cohosh products by women during pregnancy. Male offspring were maintained during the study, but not administered BCE, to detect potential effects of in utero exposure. Because black cohosh products are used by women of reproductive age, BCE was administered to female rat offspring after weaning and to female mice starting from 5 to 6 weeks of age for 2 years.