# Appendix E Supplemental Data

Tables with supplemental data can be found here: https://doi.org/10.22427/NTP-DATA-TR-603.^164^

## E.1 Perinatal and Two-year Study – Rats

### E.1.1 Data Tables

Adjusted Pup Body Weights

E01 – Animal Removal Summary by Treatment Group

E01 – Animal Removal Summary by Treatment Group – Female Pups

E01 – Animal Removal Summary by Treatment Group – Male Pups

E02 – Animals Removed from Experiment

E02 – Animals Removed from Experiment – Female Pups

E02 – Animals Removed from Experiment – Male Pups

E03 – Growth Curves

E03 – Growth Curves – Female Pups

E03 – Growth Curves – Male Pups

E03 – Growth Curves Litter Based

E04 – Mean Body Weights and Survival Table

E04 – Mean Body Weights and Survival Table – Female Pups

E04 – Mean Body Weights and Survival Table – Male Pups

E04 – Mean Body Weights and Survival Table Litter Based

E05 – Clinical Observations Summary

E12 – Animal History – Female Pups

E12 – Animal History – Male Pups

Gestational Body Weights

Lactational Body Weights

P02 – Incidence Rates of Neoplasms by Anatomic Site

P03 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site

P04 – Neoplasms by Individual Animal

P05 – Incidence Rates of Neoplasms by Anatomic Site (Systemic Lesions Abridged)

P08 – Statistical Analysis of Primary Tumors – Step Section with Litter Based Statistics

P08 – Statistical Analysis of Primary Tumors Litter Based

P09 – Non-Neoplastic Lesions by Individual Animal

P10 – Statistical Analysis of Non-Neoplastic Lesions Litter Based

P11 – Statistical Analysis of Survival Data

P11 – Statistical Analysis of Survival Data Litter Based

P14 – Individual Animal Pathology Data

P17 – Neoplasms by Individual Animal (Systemic Lesions Abridged)

P18 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site with Average Severity Grades

P40 – Survival Curves

P40 – Survival Curves – Female Pups

P40 – Survival Curves – Male Pups

PND 1 Litter Data

PND 4 and 21 Live Litter Size and Survival

R02 – Reproductive Performance Summary

### E.1.2 Individual Animal Data

Female Individual Animal Body Weight Data All Animals

Female Individual Body Weight All Animals – Female Pups

Female Individual Animal Body Weight Data All Animals – Gestation

Female Individual Animal Body Weight Data All Animals – Lactation

Female Individual Animal Clinical Observations

Female Individual Animal Neoplastic Pathology Data

Female Individual Animal Non-Neoplastic Pathology Data

Female Individual Animal Survival Data

Female Individual Animal Survival – Female Pups

Female Individual Animal Terminal Body Weight Data

Male Individual Animal Body Weight Data All Animals

Male Individual Body Weight All Animals – Male Pups

Male Individual Animal Clinical Observations

Male Individual Animal Neoplastic Pathology Data

Male Individual Animal Non-Neoplastic Pathology Data

Male Individual Animal Survival Data

Male Individual Animal Survival – Male Pups

Male Individual Animal Terminal Body Weight Data

Individual Animal Clinical Observations Data

Individual Animal Dam ID and Pup ID Data

Individual Animal Reproductive Performance Data

Individual Pup Census and Litter Weight by Sex Data

## E.2 Two-year Study (Three-month Interim Evaluation) – Mice

E01 – Animal Removal Summary by Treatment Group

E02 – Animals Removed from Experiment

E03 – Growth Curves

E04 – Mean Body Weights and Survival Table

E05 – Clinical Observations Summary

P02 – Incidence Rates of Neoplasms by Anatomic Site

P03 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site

P04 – Neoplasms by Individual Animal

P05 – Incidence Rates of Neoplasms by Anatomic Site (Systemic Lesions Abridged)

P06 – Organ Weights Summary

P08 – Statistical Analysis of Primary Tumors

P09 – Non-Neoplastic Lesions by Individual Animal

P10 – Statistical Analysis of Non-Neoplastic Lesions

P11 – Statistical Analysis of Survival Data

P12 – Organ Weights by Individual Animal

P13 – Organ Weights by Treatment Group

P14 – Individual Animal Pathology Data

P17 – Neoplasms by Individual Animal (Systemic Lesions Abridged)

P18 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site with Average Severity Grades

P40 – Survival Curves

## E.3 Two-year Study (12-month Interim Evaluation) – Mice

E01 – Animal Removal Summary by Treatment Group

E02 – Animals Removed from Experiment

E03 – Growth Curves

E04 – Mean Body Weights and Survival Table

E05 – Clinical Observations Summary

P02 – Incidence Rates of Neoplasms by Anatomic Site

P03 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site

P04 – Neoplasms by Individual Animal

P05 – Incidence Rates of Neoplasms by Anatomic Site (Systemic Lesions Abridged)

P06 – Organ Weights Summary

P08 – Statistical Analysis of Primary Tumors

P09 – Non-Neoplastic Lesions by Individual Animal

P10 – Statistical Analysis of Non-Neoplastic Lesions

P11 – Statistical Analysis of Survival Data

P12 – Organ Weights by Individual Animal

P13 – Organ Weights by Treatment Group

P14 – Individual Animal Pathology Data

P17 – Neoplasms by Individual Animal (Systemic Lesions Abridged)

P18 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site with Average Severity Grades

P40 – Survival Curves

## E.4 Hematology, Bone Marrow, and Spleen Weights for Two-year Study (3- and 12-month Interim Evaluations) – Mice

Abnormal Metarubicytes in Bone Marrow

PA06 – Organ Weights Summary

PA43 – Hematology Summary

PA50 – Bone Marrow Smear Summary

## E.5 Two-year Study – Mice

### E.5.1 Data Tables

E01 – Animal Removal Summary by Treatment Group

E02 – Animals Removed from Experiment

E03 – Growth Curves

E04 – Mean Body Weights and Survival Table

E05 – Clinical Observations Summary

P02 – Incidence Rates of Neoplasms by Anatomic Site

P03 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site

P04 – Neoplasms by Individual Animal

P05 – Incidence Rates of Neoplasms by Anatomic Site (Systemic Lesions Abridged)

P08 – Statistical Analysis of Primary Tumors

P09 – Non-Neoplastic Lesions by Individual Animal

P10 – Statistical Analysis of Non-Neoplastic Lesions

P11 – Statistical Analysis of Survival Data

P14 – Individual Animal Pathology Data

P17 – Neoplasms by Individual Animal (Systemic Lesions Abridged)

P18 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site with Average Severity Grades

P40 – Survival Curves

### E.5.2 Individual Animal Data

Female Individual Animal Body Weight Data All Animals

Female Individual Animal Clinical Observations

Female Individual Animal Neoplastic Pathology Data

Female Individual Animal Non-Neoplastic Pathology Data

Female Individual Animal Survival Data

Female Individual Animal Terminal Body Weight Data

Individual Animal Bone Marrow Smear Data

Individual Animal Hematology Data

Metarubicytes Data

## E.6 Genetic Toxicology

### E.6.1 Two-year Study (Three-month Interim Evaluation) – Mice

G04 – In Vivo Micronucleus Summary Data

Individual Animal In Vivo Micronucleus Data

### E.6.2 Genetic Toxicity Study G00058D

G06 Ames Summary Data

### E.6.3 Genetic Toxicity Study A13815

G06 Ames Summary Data

### E.6.4 Two-year Study (12-month Interim Evaluation) – Mice

G04 – In Vivo Micronucleus Summary Data

Individual Animal In Vivo Micronucleus Data