# Appendix D Genetic Toxicology

## D.1 Evaluation Protocol

National Toxicology Program (NTP) reports consider biological as well as statistical factors to determine an overall assay result. For an individual assay, the statistical procedures for data analysis are described in the following protocols. There have been instances, however, in which multiple samples of a chemical were tested in the same assay, and different results were obtained among these samples and/or among laboratories. In such cases, all the data are critically evaluated with attention given to possible protocol variations in determining the weight of evidence for an overall conclusion of chemical activity in an assay. For in vitro assays conducted with and without exogenous metabolic activation, results obtained in the absence of activation are analyzed separately from results obtained in the presence of activation. The summary table in the abstract of this Technical Report presents the Division of Translational Toxicology’s (DTT’s) scientific judgment regarding the overall evidence for activity of the chemical in an assay.

## D.2 Bacterial Mutagenicity

### D.2.1 Bacterial Mutagenicity Test Protocol

Testing procedures were modified from those originally reported by Zeiger et al.^183^ Coded samples of lot 0501-11854 of black cohosh root extract (BCE) were incubated with the Salmonella typhimurium (TA97, TA98, TA100, TA102, TA104, TA1535, TA1537) tester strains. Coded samples of lot 3012782, the same chemical lot used in the 3- and 12-month bioassays, were incubated with the S. typhimurium (TA98, TA100) and Escherichia coli WP2 uvrA (pKM101) tester strains. Incubations took place either in buffer or S9 mix (metabolic activation enzymes and cofactors from phenobarbital/benzoflavone-induced male Sprague Dawley rat liver) for 20 minutes at 37°C. Top agar supplemented with L-histidine (or tryptophan for the E. coli strain) and d-biotin was added, and the contents of the tubes were mixed and poured onto the surfaces of minimal glucose agar plates. Histidine- or tryptophan-independent mutant colonies arising on these plates were counted after incubation for 2 days at 37°C.

Each trial consisted of up to three plates of concurrent positive and negative controls and at least five doses of BCE. All strains were tested up to the previous assay limit dose of 10,000 µg/plate in the earlier study (Table D-1) and the current assay limit dose of 6,000 ug/plate in the recent study (Table D-2). Almost all trials were repeated.

In this assay, a positive response is defined as a reproducible, dose-related increase in histidine- or tryptophan-independent (revertant) colonies in any one strain/activation combination. An equivocal response is defined as an increase in revertants that is not dose-related, is not reproducible, or is not of sufficient magnitude to support a determination of mutagenicity. A negative response is obtained when no increase in revertant colonies is observed after chemical treatment. No minimum percentage or fold increase is required for a chemical to be judged positive or weakly positive, although positive calls are typically reserved for increases in mutant colonies that are at least twofold over background.

### D.2.2 Results

Results were negative in the initial assay that used both hamster and rat liver S9 over a dose range of 100–10,000 µg/plate in six strains of S. typhimurium or a dose range of 3.3–10,000 µg/plate in S. typhimurium TA97 (Table D-1). The BCE lot used in the present studies was not mutagenic in two strains of bacteria, S. typhimurium TA100 and E. coli WP2 uvrA (pKM101), but it was judged to be equivocal in S. typhimurium TA98 in the presence of induced rat liver S9 (Table D-2).

Table D-1 Mutagenicity of Black Cohosh Root Extract in Bacterial Tester Strains (Lot 0501-11854)^a^

Strain | Concentration (μg/plate) | Without S9 | Without S9 | Without S9 | With 10% Rat S9 | With 10% Rat S9 | With 30% Rat S9 | With 10% Hamster S9 | With 10% Hamster S9 | With 30% Hamster S9
TA97
| 0 | 125 ± 11.0 | 179 ± 7.3 | 124 ± 5.9 | 157 ± 17.0 | 153 ± 2.1 | 152 ± 7.3 | 176 ± 20.1 | 154 ± 13.8 | 155 ± 12.8
| 3.3 | – | – | – | – | – | – | – | 178 ± 10.0 | –
| 10 | – | – | – | – | – | – | – | 145 ± 5.8 | –
| 33 | – | – | – | – | – | – | – | 151 ± 4.0 | –
| 100 | 138 ± 7.1 | 165 ± 6.7 | 125 ± 5.2 | 154 ± 4.5 | 175 ± 9.0 | 152 ± 6.5 | 221 ± 8.2 | 141 ± 7.9 | 157 ± 8.1
| 333 | 138 ± 6.4 | 190 ± 13.9 | 124 ± 5.7 | 146 ± 9.9 | 153 ± 13.4 | 158 ± 6.9 | 202 ± 9.4 | 154 ± 6.9 | 150 ± 12.9
| 1,000 | 127 ± 2.3 | 184 ± 8.1 | 121 ± 6.2 | 161 ± 6.0 | 179 ± 1.0 | 168 ± 6.1 | 218 ± 5.9 | – | 169 ± 10.4
| 3,333 | 142 ± 2.1 | 227 ± 5.6 | 129 ± 7.2 | 160 ± 4.1 | 171 ± 25.4 | 157 ± 11.9 | 147 ± 7.6 | – | 145 ± 9.1
| 10,000 | 132 ± 6.8 | 191 ± 2.7 | 125 ± 5.8 | 201 ± 16.6 | 196 ± 6.7 | 160 ± 3.8 | 187 ± 12.9 | – | 133 ± 6.0
Trial Summary | | Negative | Equivocal | Negative | Negative | Negative | Negative | Equivocal | Negative | Negative
Positive Control^b^ | | 865 ± 101.2 | 669 ± 28.6 | 778 ± 74.4 | 1,358 ± 30.3 | 1,100 ± 78.8 | 609 ± 4.4 | 1,439 ± 127.9 | 1,384 ± 89.3 | 1,331 ± 37.8
TA98
| 0 | 14 ± 1.5 | 17 ± 1.7 | – | 22 ± 4.1 | – | 16 ± 1.8 | 28 ± 3.8 | – | 24 ± 4.5
| 100 | 12 ± 2.9 | 23 ± 0.9 | – | 19 ± 3.2 | – | 16 ± 3.8 | 24 ± 4.1 | – | 22 ± 2.6
| 333 | 11 ± 1.2 | 17 ± 2.4 | – | 23 ± 1.8 | – | 18 ± 3.3 | 28 ± 4.6 | – | 18 ± 0.9
| 1,000 | 17 ± 3.5 | 20 ± 1.2 | – | 20 ± 3.0 | – | 18 ± 0.3 | 14 ± 1.9 | – | 17 ± 2.6
| 3,333 | 15 ± 0.9 | 16 ± 1.2 | – | 24 ± 1.9 | – | 20 ± 3.3 | 25 ± 1.0 | – | 21 ± 0.6
| 10,000 | 12 ± 0.9 | 22 ± 3.2 | – | 20 ± 1.9 | – | 15 ± 3.8 | 25 ± 1.5 | – | 24 ± 1.2
Trial Summary | | Negative | Negative | – | Negative | – | Negative | Negative | – | Negative
Positive Control | | 101 ± 6.4 | 92 ± 4.0 | – | 329 ± 42.4 | – | 367 ± 19.7 | 1,240 ± 58.5 | – | 1,360 ± 27.0
TA100
| 0 | 185 ± 5.2 | 199 ± 11.9 | – | 185 ± 7.5 | – | 194 ± 2.6 | 190 ± 16.2 | – | 174 ± 3.8
| 100 | 158 ± 17.0 | 221 ± 8.2 | – | 195 ± 9.2 | – | 201 ± 12.9 | 210 ± 7.7 | – | 213 ± 6.4
| 333 | 199 ± 12.3 | 221 ± 13.7 | – | 187 ± 4.5 | – | 217 ± 21.7 | 211 ± 16.3 | – | 199 ± 4.6
| 1,000 | 164 ± 2.6 | 238 ± 5.9 | – | 218 ± 8.0 | – | 233 ± 15.5 | 225 ± 14.0 | – | 227 ± 11.8
| 3,333 | 169 ± 1.2 | 192 ± 5.9 | – | 214 ± 27.9 | – | 189 ± 14.4 | 212 ± 5.7 | – | 209 ± 9.2
| 10,000 | 173 ± 7.5 | 207 ± 20.5 | – | 219 ± 10.4 | – | 206 ± 10.7 | 243 ± 4.8 | – | 233 ± 4.9
Trial Summary | | Negative | Negative | – | Negative | – | Negative | Negative | – | Negative
Positive Control | | 642 ± 25.5 | 668 ± 15.3 | – | 843 ± 58.4 | – | 1,450 ± 184.5 | 647 ± 24.4 | – | 1,641 ± 68.0
TA102
| 0 | 314 ± 7.8 | 209 ± 3.2 | – | 274 ± 3.5 | – | 350 ± 3.6 | 297 ± 11.6 | – | 367 ± 4.2
| 100 | 304 ± 14.9 | 263 ± 17.7 | – | 252 ± 15.9 | – | 334 ± 16.2 | 235 ± 22.9 | – | 350 ± 55.2
| 333 | 302 ± 9.8 | 216 ± 6.1 | – | 265 ± 26.4 | – | 374 ± 16.6 | 265 ± 16.7 | – | 376 ± 8.7
| 1,000 | 316 ± 19.5 | 236 ± 13.2 | – | 289 ± 7.1 | – | 343 ± 19.9 | 266 ± 26.5 | – | 333 ± 20.8
| 3,333 | 309 ± 4.4 | 178 ± 17.2 | – | 319 ± 20.0 | – | 368 ± 13.9 | 304 ± 19.7 | – | 371 ± 6.0
| 10,000 | 269 ± 17.2 | 210 ± 6.9 | – | 317 ± 12.3 | – | 399 ± 14.2 | 266 ± 11.3 | – | 313 ± 11.0
Trial Summary | | Negative | Negative | – | Negative | – | Negative | Negative | – | Negative
Positive Control | | 1,022 ± 4.5 | 847 ± 55.3 | – | 1,189 ± 98.2 | – | 1,034 ± 27.1 | 992 ± 78.4 | – | 1,162 ± 21.9
TA104
| 0 | 270 ± 9.0 | 225 ± 4.4 | – | 279 ± 7.0 | – | 271 ± 21.9 | 245 ± 10.6 | – | 256 ± 8.5
| 100 | 312 ± 4.5 | 247 ± 3.9 | – | 232 ± 32.4 | – | 255 ± 12.5 | 248 ± 10.1 | – | 271 ± 5.9
| 333 | 311 ± 16.7 | 212 ± 10.7 | – | 221 ± 13.8 | – | 271 ± 4.9 | 211 ± 11.7 | – | 267 ± 24.0
| 1,000 | 336 ± 8.5 | 249 ± 12.5 | – | 260 ± 9.7 | – | 284 ± 4.7 | 253 ± 13.9 | – | 250 ± 9.6
| 3,333 | 291 ± 8.5 | 233 ± 4.1 | – | 250 ± 11.6 | – | 291 ± 16.8 | 249 ± 5.5 | – | 252 ± 13.9
| 10,000 | 302 ± 15.9 | 223 ± 7.9 | – | 302 ± 13.7 | – | 295 ± 5.6 | 265 ± 6.4 | – | 234 ± 13.7
Trial Summary | | Negative | Negative | – | Negative | – | Negative | Negative | – | Negative
Positive Control | | 976 ± 14.0 | 834 ± 20.1 | – | 1,470 ± 21.6 | – | 1,567 ± 7.2 | 943 ± 15.0 | – | 849 ± 56.7
TA1535
| 0 | 20 ± 4.9 | 14 ± 1.8 | 24 ± 5.1 | 21 ± 2.4 | – | 25 ± 2.9 | 19 ± 1.9 | – | 21 ± 1.9
| 100 | 26 ± 2.1 | 14 ± 3.2 | 19 ± 1.0 | 25 ± 1.9 | – | 20 ± 1.2 | 21 ± 1.2 | – | 23 ± 3.2
| 333 | 17 ± 2.0 | 14 ± 2.6 | 22 ± 3.8 | 23 ± 0.9 | – | 21 ± 2.7 | 24 ± 2.9 | – | 23 ± 0.7
| 1,000 | 26 ± 1.5 | 14 ± 2.7 | 24 ± 3.5 | 17 ± 3.2 | – | 24 ± 1.8 | 20 ± 0.7 | – | 24 ± 2.6
| 3,333 | 28 ± 2.1 | 15 ± 1.8 | 20 ± 3.5 | 24 ± 2.1 | – | 34 ± 3.5 | 17 ± 0.7 | – | 16 ± 1.7
| 10,000 | 37 ± 3.3 | 11 ± 1.0 | 22 ± 2.7 | 21 ± 1.7 | – | 26 ± 2.4 | 21 ± 0.7 | – | 22 ± 1.0
Trial Summary | | Equivocal | Negative | Negative | Negative | – | Negative | Negative | – | Negative
Positive Control | | 316 ± 28.7 | 183 ± 10.2 | 379 ± 27.2 | 221 ± 18.2 | – | 177 ± 6.5 | 99 ± 8.2 | – | 317 ± 35.9
TA1537
| 0 | – | – | – | 7 ± 0.9 | – | – | – | – | –
| 100 | – | – | – | 5 ± 1.5 | – | – | – | – | –
| 333 | – | – | – | 5 ± 1.5 | – | – | – | – | –
| 1,000 | – | – | – | 4 ± 0.9 | – | – | – | – | –
| 3,333 | – | – | – | 4 ± 0.7 | – | – | – | – | –
| 10,000 | – | – | – | 7 ± 0.9 | – | – | – | – | –
Trial Summary | | – | – | – | Negative | – | – | – | – | –
Positive Control | | – | – | – | 365 ± 33.5 | – | – | – | – | –

^a^ Studies performed at BioReliance Corporation. Data are presented as revertants/plate (mean ± standard error) from up to three plates; 0 μg/plate served as the solvent control (dimethyl sulfoxide).

^b^ The positive controls in the absence of metabolic activation were 9-aminoacridine (TA97), 4-nitro-o-phenylenediamine (TA98), sodium azide (TA100 and TA1535), mitomycin C (TA102), and methyl methane sulfonate (TA104). The positive controls for metabolic activation were 2-aminoanthracene (TA97, TA98, TA100, TA104, TA1535, and TA1537) and sterigmatocystin (TA102).

Table D-2 Mutagenicity of Black Cohosh Root Extract in Bacterial Tester Strains (Lot 3012782)^a^

Strain | Concentration (μg/plate) | Without S9 | Without S9 | With 10% Rat S9 | With 10% Rat S9
TA98
| 0 | 14 ± 2.1 | 17 ± 3.0 | 19 ± 0.6 | 26 ± 0.9
| 100 | 15 ± 4.5 | 16 ± 5.0 | 22 ± 3.4 | 27 ± 2.0
| 250 | 18 ± 2.7 | 18 ± 1.7 | 30 ± 3.2 | 27 ± 3.1
| 500 | 13 ± 2.2 | 19 ± 0.9 | 30 ± 1.5 | 28 ± 1.5
| 1,500 | 25 ± 0.6 | 16 ± 3.2 | 33 ± 4.7 | 29 ± 4.7
| 3,000 | 23 ± 5.0 | 18 ± 1.2 | 36 ± 5.4 | 43 ± 4.3
| 6,000 | 26 ± 4.0 | 22 ± 5.5 | 31 ± 4.8 | 45 ± 3.5
Trial Summary | | Negative | Negative | Equivocal | Equivocal
Positive Control^b^ | | 621 ± 38.9 | 607 ± 9.0 | 1,471 ± 56.0 | 1,509 ± 27.9
TA100
| 0 | 83 ± 4.7 | 88 ± 9.0 | 83 ± 3.5 | 86 ± 8.7
| 100 | 69 ± 6.4 | 76 ± 8.5 | 89 ± 5.0 | 87 ± 3.2
| 250 | 85 ± 3.0 | 79 ± 3.5 | 87 ± 3.5 | 87 ± 1.2
| 500 | 71 ± 11.4 | 79 ± 2.3 | 86 ± 3.3 | 91 ± 3.9
| 1,500 | 78 ± 5.9 | 87 ± 5.9 | 85 ± 5.5 | 95 ± 3.9
| 3,000 | 86 ± 3.7 | 83 ± 4.6 | 87 ± 8.8 | 91 ± 9.3
| 6,000 | 74 ± 8.0 | 95 ± 7.9 | 98 ± 5.0 | 97 ± 2.2
Trial Summary | | Negative | Negative | Negative | Negative
Positive Control | | 556 ± 11.1 | 595 ± 10.5 | 444 ± 25.0 | 487 ± 5.0
Escherichia coli WP2 uvrA (pKM101)
| 0 | 137 ± 4.6 | 137 ± 4.3 | 183 ± 6.2 | 205 ± 26.9
| 100 | 140 ± 6.7 | 138 ± 9.3 | 176 ± 12.1 | 198 ± 7.7
| 250 | 128 ± 6.4 | 138 ± 0.3 | 162 ± 7.6 | 185 ± 12.9
| 500 | 139 ± 1.0 | 144 ± 5.7 | 158 ± 24.2 | 184 ± 3.3
| 1,500 | 144 ± 2.6 | 129 ± 8.6 | 174 ± 6.7 | 186 ± 1.8
| 3,000 | 130 ± 3.5 | 146 ± 3.3 | 180 ± 3.3 | 190 ± 5.9
| 6,000 | 155 ± 6.5 | 148 ± 7.5 | 172 ± 1.2 | 201 ± 10.2
Trial Summary | | Negative | Negative | Negative | Negative
Positive Control | | 1,328 ± 73.7 | 1,662 ± 102.6 | 1,183 ± 79.1 | 1,680 ± 35.1

^a^ Studies performed at Integrated Laboratory Systems, LLC. Data are presented as revertants/plate (mean ± standard error) from two plates; 0 μg/plate served as the solvent control (dimethyl sulfoxide).

^b^ The positive controls in the absence of metabolic activation were 2-nitrofluorene (TA98), sodium azide (TA100), and 4-nitroquinolone-N-oxide (E. coli). The positive controls for metabolic activation were 2-aminoanthracene (TA98, E. coli) and benzo[a]pyrene (TA100).

## D.3 Micronucleus Assay

### D.3.1 Peripheral Blood Micronucleus Test Protocol

At the 3-month and 12-month interim evaluations of BCE, blood samples (approximately 200 μL) were collected from female mice, placed in ethylenediaminetetraacetic acid (EDTA)-coated tubes, and shipped overnight to the testing laboratory. Upon arrival, blood samples were fixed in ultracold methanol using a MicroFlowPLUS Kit (Litron Laboratories, Rochester, NY) according to the manufacturer’s instructions. Fixed samples were stored in a −80°C freezer until analysis. Thawed blood samples were analyzed for frequency of micronucleated immature erythrocytes (i.e., reticulocytes or polychromatic erythrocytes [PCEs]) and mature erythrocytes (i.e., normochromatic erythrocytes [NCEs]) using a flow cytometer^184^; both the mature and the immature erythrocyte populations can be analyzed separately by employing special cell surface markers to differentiate the two cell types. In mice, both the mature and immature erythrocyte populations can be evaluated for micronucleus frequency because the mouse spleen does not sequester and eliminate damaged erythrocytes. Damaged erythrocytes achieve steady state in the peripheral blood of mice after 4 weeks of continuous exposure. Approximately 20,000 PCEs and 1 × 10^6^ NCEs were analyzed per animal for frequency of micronucleated cells, and the percentage of immature erythrocytes (% PCE) was calculated as a measure of bone marrow toxicity resulting from BCE exposure.

Prior experience with the large number of cells scored using flow-cytometric scoring techniques^185^ suggests it is reasonable to assume that the proportion of micronucleated reticulocytes is approximately normally distributed. The statistical tests selected for trend and for pairwise comparisons with the vehicle control group depend on whether the variances among the groups are equal. The Levene test at α = 0.05 is used to test for equal variances. In the case of equal variances, linear regression is used to test for a linear trend with dose, and the Williams test^142,143^ is used to test for pairwise differences between each dosed group and the vehicle control group. In the case of unequal variances, the Jonckheere test^147^ is used to test for linear trend, and the Dunn test^146^ is used for pairwise comparisons of each dosed group with the vehicle control group. To correct for multiple pairwise comparisons, the p value for each comparison with the vehicle control group is multiplied by the number of comparisons made. In the event that this product is >1.00, it is replaced with 1.00. Trend tests and pairwise comparisons with the vehicle control group are considered statistically significant at p ≤ 0.025.

In the micronucleus test, it is preferable to base a positive result on the presence of both a positive trend as well as at least one significantly elevated dosed group compared with the corresponding vehicle control group. In addition, historical control data are used to evaluate the biological significance of any observed response. Both statistical significance and biological significance are considered when arriving at a call. The presence of either a positive trend or a single significant dosed group generally results in an equivocal call. The absence of both a trend and any significant differences between dosed groups and the vehicle control group results in a negative call. Ultimately, the scientific staff determines the final call after considering the results of statistical analyses, reproducibility of any effects observed (in acute studies), and the magnitudes of those effects.

### D.3.2 Results

At the 3-month interim evaluation, a significant, dose-related increase in micronucleated erythrocytes was observed (Table 12). At the 12-month evaluation, a significant, dose-related increase in the frequencies of micronucleated erythrocytes was also observed, and the magnitude of response was similar to that observed at the 3-month evaluation (Table 12). No significant changes were observed in the percentage of immature erythrocytes (% PCE) in the BCE-dosed mice at either evaluation.