# Appendix B Ingredients, Nutrient Composition, and Contaminant Levels in NIH-07 Rat and NTP-2000 Rat and Mouse Ration

## B.1 NIH-07 Feed

Table B-1 Ingredients of NIH-07 Rat Ration

Ingredients | Percent by Weight
Ground Hard Winter Wheat | 23.00
Ground #2 Yellow Shelled Corn | 24.25
Wheat Middlings | 10.0
Oat Hulls | 0.0
Alfalfa Meal (Dehydrated, 17% Protein) | 4.0
Purified Cellulose | 0.0
Soybean Meal (47% Protein) | 12.0
Fish Meal (62% Protein) | 10.0
Corn Oil (without Preservatives) | 0.0
Soy Oil (without Preservatives) | 2.5
Dried Brewer’s Yeast | 2.0
Calcium Carbonate (USP) | 0.5
Vitamin Premix^a^ | 0.25
Mineral Premix^b^ | 0.15
Calcium Phosphate, Dibasic (USP) | 1.25
Sodium Chloride | 0.5
Choline Chloride (70% Choline) | 0.10
Dried Skim Milk | 5.0
Dried Molasses | 1.50
Corn Gluten Meal (60% Protein) | 3.00
Methionine | 0.0

USP = United States Pharmacopeia.

^a^ Wheat middlings as carrier.

^b^ Calcium carbonate as carrier.

Table B-2 Vitamins and Minerals in NIH-07 Rat Ration

| Amount^a^ | Source
Vitamins
Vitamin A | 6,062 IU | Stabilized vitamin A palmitate or acetate
Vitamin D | 5,070 IU | D-activated animal sterol
Vitamin K | 3.1 mg | Menadione sodium bisulfite complex
Vitamin E | 22 IU | α-Tocopheryl Acetate
Niacin | 33 mg | –
Folic Acid | 2.4 mg | –
d-Pantothenic Acid | 19.8 mg | d-Calcium pantothenate
Riboflavin | 3.8 mg | –
Thiamine | 11 mg | Thiamine mononitrate
B_12_ | 50 µg | –
Pyridoxine | 6.5 mg | Pyridoxine hydrochloride
Biotin | 0.15 mg | d-Biotin
Minerals
Iron | 132 mg | Iron sulfate
Zinc | 18 mg | Zinc oxide
Manganese | 66 mg | Manganese oxide
Copper | 4.4 mg | Copper sulfate
Iodine | 2.0 mg | Calcium iodate
Cobalt | 0.44 mg | Cobalt carbonate

^a^ Per kg of finished diet.

Table B-3 Nutrient Composition of NIH-07 Rat Ration

Nutrient | Mean ± Standard Deviation | Range | Number of Samples
Protein (% by Weight) | 23.3 ± 0.698 | 22.4–23.9 | 4
Crude Fat (% by Weight) | 5.53 ± 0.096 | 5.4–5.6 | 4
Crude Fiber (% by Weight) | 3.248 ± 0.205 | 3.1–3.55 | 4
Ash (% by Weight) | 6.09 ± 0.285 | 5.83–6.44 | 4
Amino Acids (% of Total Diet)
Arginine | 1.278 ± 0.343 | 0.258–1.49 | 11
Cystine | 0.307 ± 0.059 | 0.153–0.372 | 11
Glycine | 1.065 ± 0.289 | 0.217–1.31 | 11
Histidine | 0.482 ± 0.121 | 0.125–0.553 | 11
Isoleucine | 0.914 ± 0.233 | 0.214–1.03 | 11
Leucine | 1.873 ± 0.485 | 0.423–2.13 | 11
Lysine | 1.140 ± 0.345 | 0.111–1.32 | 11
Methionine | 0.453 ± 0.117 | 0.102–0.515 | 11
Phenylalanine | 1.023 ± 0.245 | 0.286–1.12 | 11
Threonine | 0.850 ± 0.228 | 0.168–0.961 | 11
Tryptophan | 0.259 ± 0.064 | 0.076–0.326 | 11
Tyrosine | 0.801 ± 0.200 | 0.209–0.894 | 11
Valine | 1.055 ± 0.264 | 0.262–1.17 | 11
Essential Fatty Acids (% of Total Diet)
Linoleic | 2.436 ± 0.489 | 0.199–3.77 | 11
Linolenic | 0.367 ± 0.397 | 0.214–1.56 | 11
Vitamins
Vitamin A (IU/kg) | 5,438 ± 369 | 5,140–5,900 | 4
α-Tocopherol (ppm) | 6,097 ± 20,067 | 31.36–66,600 | 11
Thiamine (ppm)^a^ | 14.65 ± 2.588 | 12.1–18.1 | 4
Riboflavin (ppm) | 13.54 ± 4.438 | 4.2–19.8 | 11
Niacin (ppm) | 95.02 ± 16.30 | 51.9–112.0 | 11
Pantothenic Acid (ppm) | 40.69 ± 12.76 | 3.8–51.1 | 11
Pyridoxine (ppm)^a^ | 11.74 ± 4.81 | 0.42–19.7 | 11
Folic Acid (ppm) | 2.38 ± 0.571 | 1.37–3.09 | 11
Biotin (ppm) | 0.300 ± 0.187 | 0.0–0.638 | 11
B_12_ (ppb) | 45.27 ± 15.14 | 4.0–61.6 | 11
Choline (as Chloride) (ppm) | 1,719.0 ± 386.0 | 700.0–2,200.0 | 11
Minerals
Calcium (%) | 1.034 ± 0.048 | 0.966–1.08 | 4
Phosphorus (%) | 0.871 ± 0.047 | 0.816–0.929 | 4
Potassium (%) | 0.762 ± 0.226 | 0.088–0.88 | 11
Chloride (%) | 0.656 ± 0.102 | 0.411–0.8 | 11
Sodium (%) | 0.409 ± 0.112 | 0.318–0.721 | 11
Magnesium (%) | 0.171 ± 0.053 | 0.0162–0.218 | 11
Iron (ppm) | 353.3 ± 117.5 | 35.7–469.0 | 11
Manganese (ppm) | 82.88 ± 27.28 | 3.53–104.0 | 11
Zinc (ppm) | 58.75 ± 20.3 | 4.74–89.2 | 11
Copper (ppm) | 12.91 ± 4.73 | 0.683–21.1 | 11
Iodine (ppm) | 1.647 ± 1.088 | 0.0–3.45 | 11
Chromium (ppm) | 3.95 ± 0.035 | 3.89–4.0 | 9
Cobalt (ppm) | 0.470 ± 0.296 | 0.01–0.963 | 11

^a^ As hydrochloride.

Table B-4 Contaminant Levels in NIH-07 Rat Ration

| Mean ± Standard Deviation | Range | Number of Samples
Contaminants
Arsenic (ppm) | 0.407 ± 0.093 | 0.315–0.535 | 4
Cadmium (ppm) | 0.067 ± 0.011 | 0.057–0.082 | 4
Lead (ppm) | 0.138 ± 0.070 | 0.10–0.243 | 4
Mercury (ppm) | 0.016 ± 0.006 | 0.012–0.024 | 4
Selenium (ppm) | 0.427 ± 0.068 | 0.337–0.493 | 4
Aflatoxins (ppb)^a^ | <5.0 | – | 4
Nitrate Nitrogen (ppm)^b^ | 17.63 ± 7.40 | 10.4–24.4 | 4
Nitrite Nitrogen (ppm)^a,b^ | <0.61 | – | 4
BHA (ppm)^a,c^ | <1.0 | – | 4
BHT (ppm)^a,c^ | <1.0 | – | 4
Aerobic Plate Count (CFU/g) | <10.0 | – | 4
Coliform (MPN/g) | <3.0 | – | 4
Escherichia coli (MPN/g)^a^ | <10.0 | – | 4
Salmonella sp. (MPN/g) | Negative | – | 4
Total Nitrosamines (ppb)^d^ | 6.15 ± 4.28 | 0.0–9.8 | 4
N,Nitrosodimethylamine (ppb)^d^ | 1.65 ± 1.97 | 0.0–3.9 | 4
N,Nitrosopyrrolidine (ppb)^d^ | 4.5 ± 4.14 | 0.0–9.8 | 4
Pesticides (ppm)
α-BHC^a^ | <0.01 | – | 4
β-BHC^a^ | <0.02 | – | 4
γ-BHC^a^ | <0.01 | – | 4
δ-BHC^a^ | <0.01 | – | 4
Heptachlor^a^ | <0.01 | – | 4
Aldrin^a^ | <0.01 | – | 4
Heptachlor Epoxide^a^ | <0.01 | – | 4
DDE^a^ | <0.01 | – | 4
DDD^a^ | <0.01 | – | 4
DDT^a^ | <0.01 | – | 4
HCB^a^ | <0.01 | – | 4
Mirex^a^ | <0.01 | – | 4
Methoxychlor^a^ | <0.05 | – | 4
Dieldrin^a^ | <0.01 | – | 4
Endrin^a^ | <0.01 | – | 4
Telodrin^a^ | <0.01 | – | 4
Chlordane^a^ | <0.05 | – | 4
Toxaphene^a^ | <0.10 | – | 4
Estimated PCBs^a^ | <0.20 | – | 4
Ronnel^a^ | <0.01 | – | 4
Ethion^a^ | <0.02 | – | 4
Trithion^a^ | <0.05 | – | 4
Diazinon^a^ | <0.10 | – | 4
Methyl Chlorpyrifos | 0.054 ± 0.032 | 0.02–0.096 | 4
Methyl Parathion^a^ | <0.02 | – | 4
Ethyl Parathion^a^ | <0.02 | – | 4
Malathion | 0.040 ± 0.039 | 0.02–0.10 | 4
Endosulfan I^a^ | <0.01 | – | 4
Endosulfan II^a^ | <0.01 | – | 4
Endosulfane Sulfate^a^ | <0.03 | – | 4

All samples were irradiated.

BHA = butylated hydroxyanisole; BHT = butylated hydroxytoluene; CFU = colony-forming units; MPN = most probable number; BHC = hexachlorocyclohexane or benzene hexachloride; DDE = dichlorodiphenyldichloroethylene; DDD = dichlorodiphenyldichloroethane; DDT = dichlorodiphenyltrichloroethane; HCB = hexachlorobenzene; PCB = polychlorinated biphenyl.

^a^ All values were below the detection limit. The detection limit is given as the mean.

^b^ Sources of contamination include alfalfa, grains, and fish meal.

^c^ Sources of contamination include soy oil and fish meal.

^d^ All values were corrected for percent recovery.

## B.2 NTP-2000 Feed

Table B-5 Ingredients of NTP-2000 Rat and Mouse Ration

Ingredients | Percent by Weight
Ground Hard Winter Wheat | 23.00
Ground #2 Yellow Shelled Corn | 22.44
Wheat Middlings | 15.0
Oat Hulls | 8.5
Alfalfa Meal (Dehydrated, 17% Protein) | 7.5
Purified Cellulose | 5.5
Soybean Meal (49% Protein) | 4.0
Fish Meal (60% Protein) | 4.0
Corn Oil (without Preservatives) | 3.0
Soy Oil (without Preservatives) | 3.0
Dried Brewer’s Yeast | 1.0
Calcium Carbonate (USP) | 0.9
Vitamin Premix^a^ | 0.5
Mineral Premix^b^ | 0.5
Calcium Phosphate, Dibasic (USP) | 0.4
Sodium Chloride | 0.3
Choline Chloride (70% Choline) | 0.26
Methionine | 0.2

USP = United States Pharmacopeia.

^a^ Wheat middlings as carrier.

^b^ Calcium carbonate as carrier.

Table B-6 Vitamins and Minerals in NTP-2000 Rat and Mouse Ration

| Amount^a^ | Source
Vitamins
Vitamin A | 4,000 IU | Stabilized vitamin A palmitate or acetate
Vitamin D | 1,000 IU | D-activated animal sterol
Vitamin K | 1.0 mg | Menadione sodium bisulfite complex
α-Tocopheryl Acetate | 100 IU | –
Niacin | 23 mg | –
Folic Acid | 1.1 mg | –
d-Pantothenic Acid | 10 mg | d-Calcium pantothenate
Riboflavin | 3.3 mg | –
Thiamine | 4 mg | Thiamine mononitrate
B_12_ | 52 µg | –
Pyridoxine | 6.3 mg | Pyridoxine hydrochloride
Biotin | 0.2 mg | d-Biotin
Minerals
Magnesium | 514 mg | Magnesium oxide
Iron | 35 mg | Iron sulfate
Zinc | 12 mg | Zinc oxide
Manganese | 10 mg | Manganese oxide
Copper | 2.0 mg | Copper sulfate
Iodine | 0.2 mg | Calcium iodate
Chromium | 0.2 mg | Chromium acetate

^a^ Per kg of finished diet.

Table B-7 Nutrient Composition of NTP-2000 Rat and Mouse Ration

Nutrient | Mean ± Standard Deviation | Range | Number of Samples
Protein (% by Weight) | 14.6 ± 0.434 | 13.9–15.5 | 32
Crude Fat (% by Weight) | 8.42 ± 0.328 | 7.7–9.2 | 32
Crude Fiber (% by Weight) | 9.35 ± 0.671 | 8.09–11.8 | 32
Ash (% by Weight) | 4.89 ± 0.133 | 4.66–5.14 | 32
Amino Acids (% of Total Diet)
Arginine | 0.806 ± 0.074 | 0.67–0.97 | 30
Cystine | 0.220 ± 0.021 | 0.15–0.25 | 30
Glycine | 0.702 ± 0.037 | 0.62–0.8 | 30
Histidine | 0.341 ± 0.069 | 0.27–0.68 | 30
Isoleucine | 0.548 ± 0.039 | 0.43–0.66 | 30
Leucine | 1.096 ± 0.062 | 0.96–1.24 | 30
Lysine | 0.070 ± 0.103 | 0.31–0.86 | 30
Methionine | 0.409 ± 0.041 | 0.26–0.49 | 30
Phenylalanine | 0.623 ± 0.046 | 0.471–0.72 | 30
Threonine | 0.513 ± 0.041 | 0.43–0.61 | 30
Tryptophan | 0.156 ± 0.026 | 0.1–0.2 | 30
Tyrosine | 0.423 ± 0.065 | 0.28–0.54 | 30
Valine | 0.666 ± 0.039 | 0.55–0.73 | 30
Essential Fatty Acids (% of Total Diet)
Linoleic | 3.939 ± 0.233 | 3.49–4.55 | 30
Linolenic | 0.306 ± 0.030 | 0.21–0.368 | 30
Vitamins
Vitamin A (IU/kg) | 3,941 ± 664 | 2,820–5,450 | 32
Vitamin D (IU/kg) | 1,000^a^ | – | –
α-Tocopherol (ppm) | 2,376 ± 12,602 | 13.6–69,100 | 30
Thiamine (ppm)^b^ | 9.86 ± 13.0 | 5.8–81.0 | 32
Riboflavin (ppm) | 8.17 ± 2.792 | 4.2–17.5 | 30
Niacin (ppm) | 79.19 ± 8.497 | 66.4–98.2 | 30
Pantothenic Acid (ppm) | 26.33 ± 10.87 | 17.4–81.0 | 30
Pyridoxine (ppm)^b^ | 9.719 ± 2.018 | 6.44–14.3 | 30
Folic Acid (ppm) | 1.6 ± 0.440 | 1.15–3.27 | 30
Biotin (ppm) | 0.330 ± 0.097 | 0.2–0.704 | 30
B_12_ (ppb) | 50.06 ± 34.24 | 18.3–174.0 | 30
Choline (as Chloride) (ppm) | 2,572 ± 634 | 1,160–3,790 | 30
Minerals
Calcium (%) | 0.906 ± 0.061 | 0.697–1.02 | 32
Phosphorus (%) | 0.556 ± 0.0233 | 0.51–0.615 | 32
Potassium (%) | 0.668 ± 0.287 | 0.626–0.733 | 30
Chloride (%) | 0.391 ± 0.44 | 0.3–0.517 | 30
Sodium (%) | 0.194 ± 0.027 | 0.153–0.283 | 30
Magnesium (%) | 0.217 ± 0.053 | 0.185–0.49 | 30
Iron (ppm) | 190.43 ± 36.11 | 135–311 | 30
Manganese (ppm) | 50.02 ± 9.27 | 21.0–73.1 | 30
Zinc (ppm) | 56.81 ± 25.25 | 42.5–184 | 30
Copper (ppm) | 7.61 ± 2.46 | 3.21–16.3 | 30
Iodine (ppm) | 0.514 ± 0.217 | 0.0–0.972 | 30
Chromium (ppm) | 1.119 ± 1.157 | 0.33–3.97 | 30
Cobalt (ppm) | 0.219 ± 0.150 | 0.086–0.864 | 30

^a^ From formulation.

^b^ As hydrochloride.

Table B-8 Contaminant Levels in NTP-2000 Rat and Mouse Ration

| Mean ± Standard Deviation | Range | Number of Samples
Contaminants
Arsenic (ppm) | 0.206 ± 0.045 | 0.143–0.312 | 32
Cadmium (ppm) | 0.064 ± 0.080 | 0.0150–0.54 | 32
Lead (ppm) | 0.161 ± 0.202 | 0.066–1.19 | 32
Mercury (ppm) | 0.011 ± 0.003 | 0.01–0.026 | 32
Selenium (ppm) | 0.172 ± 0.024 | 0.097–0.23 | 32
Aflatoxins (ppb)^a^ | <5.0 | – | 32
Nitrate Nitrogen (ppm)^b^ | 17.47 ± 8.02 | 10.0–45.9 | 32
Nitrite Nitrogen (ppm)^a,b^ | <0.61 | – | 32
BHA (ppm)^c^ | 1.12 ± 0.665 | 1.0–4.76 | 32
BHT (ppm)^c^ | 1.03 ± 0.156 | 1.0–1.88 | 32
Aerobic Plate Count (CFU/g) | 14.844 ± 18.556 | 10–110 | 32
Coliform (MPN/g) | <3 | – | 32
Escherichia coli (MPN/g)^a^ | <10 | – | 32
Salmonella sp. (MPN/g) | Negative | – | 32
Total Nitrosamines (ppb)^d^ | 8.66 ± 4.70 | 0.0–19.9 | 32
N-Nitrosodimethylamine (ppb)^d^ | 1.46 ± 1.21 | 0.0–4.8 | 32
N-Nitrosopyrrolidine (ppb)^d^ | 7.28 ± 4.10 | 0.0–18.6 | 32
Pesticides (ppm)
α-BHC^a^ | <0.01 | – | 32
β-BHC^a^ | <0.02 | – | 32
γ-BHC^a^ | <0.01 | – | 32
δ-BHC^a^ | <0.01 | – | 32
Heptachlor^a^ | <0.01 | – | 32
Aldrin^a^ | <0.01 | – | 32
Heptachlor Epoxide^a^ | <0.01 | – | 32
DDE^a^ | <0.01 | – | 32
DDD^a^ | <0.01 | – | 32
DDT^a^ | <0.01 | – | 32
HCB^a^ | <0.01 | – | 32
Mirex^a^ | <0.01 | – | 32
Methoxychlor^a^ | <0.05 | – | 32
Dieldrin^a^ | <0.01 | – | 32
Endrin^a^ | <0.01 | – | 32
Telodrin^a^ | <0.01 | – | 32
Chlordane^a^ | <0.05 | – | 32
Toxaphene^a^ | <0.01 | – | 32
Estimated PCBs^a^ | <0.20 | – | 32
Ronnel^a^ | <0.01 | – | 32
Ethion^a^ | <0.02 | – | 32
Trithion^a^ | <0.05 | – | 32
Diazinon^a^ | <0.10 | – | 32
Methyl Chlorpyrifos | 0.113 ± 0.141 | 0.02–0.686 | 32
Methyl Parathion^a^ | <0.02 | – | 32
Ethyl Parathion^a^ | <0.02 | – | 32
Malathion | 0.099 ± 0.091 | 0.02–0.344 | 32
Endosulfan I^a^ | <0.01 | – | 32
Endosulfan II^a^ | <0.01 | – | 32
Endosulfan Sulfate^a^ | <0.03 | – | 32

All samples were irradiated.

BHA = butylated hydroxyanisole; BHT = butylated hydroxytoluene; CFU = colony-forming units; MPN = most probable number; BHC = hexachlorocyclohexane or benzene hexachloride; DDE = dichlorodiphenyldichloroethylene; DDD = dichlorodiphenyldichloroethane; DDT = dichlorodiphenyltrichloroethane; HCB = hexachlorobenzene; PCB = polychlorinated biphenyl.

^a^ All values were below the detection limit. The detection limit is given as the mean.

^b^ Sources of contamination include alfalfa, grains, and fish meal.

^c^ Sources of contamination include soy oil and fish meal.

^d^ All values were corrected for percent recovery.