# Appendix A Chemical Characterization and Dose Formulation Studies

## A.1 Procurement and Characterization

### A.1.1 Black Cohosh Root Extract

Black cohosh root extract (BCE) was obtained from PlusPharma, Inc. (Vista, CA) in a single lot (3012782). The lot was manufactured by Frutarom Switzerland Ltd. (Wädenswil, Switzerland). According to the manufacturer’s certificate of analysis, lot 3012782 was a 50% aqueous ethanolic extract standardized to 7.8% (w/w) total triterpene glycosides. Identity, purity, and stability analyses were conducted by the study laboratory Battelle (Columbus, OH). Reports on analyses performed in support of the BCE studies are on file at the National Institute of Environmental Health Sciences (NIEHS).

The BCE test lot was a light-brown powder. It was confirmed to be authentic black cohosh by multiple laboratories using high-performance thin-layer chromatography and DNA barcoding. Fourier transform infrared (IR) spectroscopy detected the presence of phenolic compounds, as well as plant components such as sugars, terpenes, and glycosides. Proton-induced X-ray emission spectroscopy analysis conducted by Element Analysis Corporation (Lexington, KY) indicated that the BCE was composed almost entirely of carbon (69.5%), hydrogen (11.7%), and oxygen (15.4%). Potassium (2.5%), magnesium (0.3%), and calcium (0.3%) were also detected. Water content in lot 3012782 was determined to be <7.9% via Karl Fisher analysis (Prevalere Life Sciences, Inc., Whitesboro, NY) and weight loss on drying.

Analysis of the extract by liquid chromatography (LC) coupled with quadrupole time-of-flight mass spectrometry (MS) or quadrupole ion trap MS identified up to 39 constituents belonging to triterpene glycoside, phenolic acids, and alkaloid classes. Twenty-four constituents were identified with high confidence, whereas the remaining 15 constituents were classified with tentative identification due to lower confidence stemming from lack of authentic standards, low levels present to obtain a representative spectrum, presence of multiple isomers, or less than ideal library matches. The constituents definitively identified and for which authentic standards are available (caffeic acid, ferulic acid, isoferulic acid, actein, 23-epi-26-deoxyactein [27-deoxyactein], cimifugin, allocryptopine, cimicifugoside H-1, cimiracemoside C, 26-deoxycimicifugoside, magnoflorine, and prim-o-glucosylcimifugin) were quantified by standard addition^182^ followed by LC coupled with tandem mass spectrometry. Quantitation of analytes by LC-MS/MS showed that the extract contained (w/w) 0.28% caffeic acid, 0.04% ferulic acid, 0.70% isoferulic acid, 0.47% actein, 2.09% 23-epi-26-deoxyactein (27-deoxyactein), 2.13% cimiracemoside C, 0.08% 26-deoxycimicifugoside, and 0.01% magnoflorine. Cimifugin, prim-o-glucosylcimifugin, allocryptopine, and cimifugoside H-1 were not quantifiable and were estimated to be <0.01% in the extract. The measured constituents accounted for approximately 5.8% of the total extract weight.

An aliquot of the test lot was evaluated for environmental contaminants by Covance Laboratories, Inc. (Madison, WI). The heavy metals arsenic, cadmium, and lead were present at low levels, below the threshold limits for botanical dietary supplements (5, 0.3, and 10 ppm, respectively).^119,120^ Antimony and mercury were not present above the limits of quantitation. Ochratoxin and zearalenone were not present in concentrations at or above the limits of quantitation. Of >300 pesticides screened, only chlorpropham (0.012 ppm) and 2-phenylphenol (0.016 ppm) were detected, and these were present at concentrations below the lowest respective U.S. Environmental Protection Agency residue tolerance levels (0.06 and 5 ppm, respectively).^121,122^ Aflatoxins B_1_, B_2_, G_1_, and G_2_ and the pesticide imazilil could not be accurately detected because of matrix interferences. All other pesticides were determined to be below the limits of quantitation.

A comparison of high-performance liquid chromatography (HPLC)-charged aerosol detection chromatographic profiles of BCE lot 3012782 with root extract reference material and a black cohosh product available to the public in the United States showed that the chemical profiles were similar.

Accelerated stability studies were conducted using HPLC with ultraviolet (UV) detection (Table A-1) with isoferulic acid as a marker. Samples of lot 3012782 were stored sealed in amber glass bottles for 14 days at frozen (−20°C), refrigerated (5°C), room (25°C), and elevated (60°C) temperatures. Stability was confirmed for at least 14 days at ≤25°C. Further details identifying the test lot as BCE, as well as a thorough description of its composition, are available in a separate publication by Waidyanatha et al.^123^

Six plastic bags of the BCE test lot were originally received. Each was double bagged and rolled for 5 minutes to homogenize. All bags were then transferred to 4 L plastic bottles. Samples were removed and stored to serve as analytical standards (room temperature), reference standards (−20°C), and an archive sample (−20°C). The remaining bulk test article was sealed and stored at room temperature. Reanalysis of the bulk chemical, using isoferulic acid as the marker, was performed once (mice) or three times (rats) before the start of the study, four times during the study, and one time after study termination using HPLC/UV (Table A-1). No degradation of the bulk test article was detected by analysis of the marker constituent, comparison of the constituent profile with frozen reference material, or the appearance of the bulk material.

### A.1.2 Methylcellulose

Methylcellulose used to make the 0.5% aqueous vehicle for gavage formulations was obtained from Spectrum (Gardena, CA) in two lots (2CB0045 and 2AJ0439). The identity of methylcellulose was confirmed by the study laboratory using IR spectroscopy. The IR spectra were consistent with a reference spectrum from the Wiley Hummel Surfactants Library (No. 1003) (Figure A-2). Methoxy content was measured by Galbraith Laboratories, Inc. (Knoxville, TN). The average methoxy contents of lots 2CB0045 and 2AJ0439 were 31.0% and 30.8%, respectively. Methoxy content was reanalyzed at 6-month intervals during the study to determine the methoxy group content. Lot 2AJ0439 was acceptable for use. Lot 2CB0045 was approved for use by the National Toxicology Program (NTP) despite having a methoxy group value approximately 0.3% above the NTP acceptance criterion of 31.5% at multiple measurement intervals.

Water from the City of Columbus municipal supply was deionized at Battelle and used to prepare the 0.5% (w/v) aqueous methylcellulose vehicle. Other than analyses conducted by the City of Columbus to assure the acceptability of the water as a potable supply, no further analyses of the municipal water supply or the deionized water supply were performed.

## A.2 Preparation and Analysis of Dose Formulations

Dose formulations of BCE (lot 3012782) in 0.5% aqueous methylcellulose were prepared at the study laboratory following the protocols outlined in Table A-2. For the rat study, formulations were prepared at 0, 15, 50, and 150 mg/mL (38 preparations; May 2012–June 2014). For the mouse study, formulations were prepared at 0, 3, 10, 30, and 100 mg/mL (36 preparations; March 2012–April 2014).

The homogeneity and stability of the dose formulations were determined by the study laboratory using HPLC/UV (Table A-1). Isoferulic acid was used as the marker for BCE formulation analysis. Homogeneity was evaluated using 3, 20, 100, and 200 mg/mL formulations and was confirmed at these doses. Stability of the 3, 30, and 100 mg/mL formulations was investigated using marker constituents actein, 27-deoxyactein, isoferulic acid, or cimiracemoside C prior to and following study termination. Stability studies were conducted at room temperature (approximately 25°C) and refrigerated temperature (approximately 5°C). Stability of the 3, 30, and 100 mg/mL dose formulations was confirmed for up to 42 days in sealed, refrigerated, amber glass bottles. In addition, a simulated animal room stability study was conducted with the 3, 30, and 100 mg/mL dose formulations stored at room temperature for 7 days and exposed to simulated usage conditions. These formulations were stable under simulated animal room conditions for at least 3 hours. The formulations for the 2-year rat and mouse studies were stored in sterile, clear glass, straight-sided bottles under inert headspace at 2°C–8°C (refrigerated).

Analyses of preadministration and postadministration dose formulations for the 2-year studies of BCE were conducted by the study laboratory using HPLC/UV (Table A-1), with isoferulic acid as the marker. All preadministration dose formulations for BCE were within 10% of the target concentrations (Table A-3, Table A-4). All postadministration samples in the rat and mouse studies were within 10% of the target concentrations, with one exception from the mouse study: the 3 mg/mL formulation concentration prepared on November 7, 2013, was below the limit of quantitation (BLOQ) when analyzed on December 12, 2013 (Table A-3, Table A-4). To investigate this result, the following samples from the same formulation batch were analyzed: an archive sample collected at the time of formulation preparation (stored frozen), a retention sample collected at the time of formulation receipt (stored frozen), and two additional bottles that had been used to dose animals (stored refrigerated). All samples were within 5% of the preadministration value.

To determine whether degradation was an issue with other formulation batches, the 3 mg/mL formulation in the next set of formulations (prepared December 19, 2013) was measured both immediately before and after administration to mice. All resulting concentrations were within 10% of the target values (Table A-4). Furthermore, all other 3 mg/mL postadministration values throughout the entire 2-year study were within 10% of the target values. Therefore, the BLOQ findings from the original animal room analysis of this batch were considered anomalous and unlikely to affect the study results.

The dose formulations were used within 42 days during the first 11 months of the studies. Before dose administration on April 13, 2013, unidentified particles resembling mold were observed in the 15 mg/mL rat dose formulation and the 3 and 10 mg/mL mouse dose formulation. To determine whether storing the formulation frozen would prevent mold growth, an experiment was conducted by storing formulations prepared May 2, 2013, at approximately −20°C in polycarbonate jars for 26 days. The frozen formulations were then thawed and analyzed using HPLC/UV (Table A-1). All dose formulations were within 10% of the target concentrations, and the results indicated no differences between refrigerated and frozen samples (Table A-3, Table A-4). Following this finding, subsequent dose formulations were used within 21 days and included backup formulations that were stored frozen. There were no further reports of mold growth in the dose formulations during the 2-year studies.

Table A-1 Liquid Chromatography Systems Used in the Two-year Gavage Studies of Black Cohosh Root Extract

Chromatography | Detection System | Column | Mobile Phase
System A
High-performance liquid chromatography | Ultraviolet (317 nm) | Phenomenex Hypersil Phenyl (250 mm × 4.6 mm ID, 5 μm particle size) | A: 1% Formic Acid:ACN (90:10) B: 1% Formic Acid:ACN (40:60) Gradient program: A:B 100:0 to 40:60 in 30 min; 40:60 to 0:100 in 30 min; 0:100 to 100:0 in 0.1 min, hold at 100:0 for 9.9 min 1.0 mL/min flow rate

ID = internal diameter; ACN = acetonitrile.

Table A-2 Preparation and Storage of Dose Formulations Administered to Rats and Mice in the Two-year Gavage Studies of Black Cohosh Root Extract

Preparation
For the 0 mg/mL formulation, blank 0.5% (w/v) aqueous methylcellulose vehicle was used. For remaining formulations, the appropriate amount of black cohosh root extract was weighed into a tared mixing container that had been previously calibrated to the appropriate volume necessary for the formulation concentration. With the mixing container still on the balance, enough vehicle was added to wet the test article and create a slurry without excess foaming. Vehicle was then slowly added to the mixing container to the final target weight depending on the density of each formulation. The resulting mixture was checked to confirm the final weight agreed with the final volume calibration mark on the mixing container. A stir bar was added to each mixing container, and the formulations were stirred on a stir plate for approximately 10 minutes at a speed that produced a vortex without creating excess foam. To ensure homogeneity, the formulations were capped and stirred on a stir plate for approximately 2 hours or until the batch was visibly homogenous. The formulations were dispensed into the appropriate number of labeled 250 mL (rat) or 120 mL (mouse) sterile, clear glass, straight-sided bottles. The bottles were filled with an inert headspace and sealed with Teflon^®^-lined lids.
Chemical Lot Number
3012782 (PlusPharma, Inc., Vista, CA)
Maximum Storage Time
42 days
Storage Conditions
Stored in sterile, clear glass, straight-sided bottles under inert headspace at 2°C to 8°C (refrigerated).
Study Laboratory
Battelle (Columbus, OH)

Table A-3 Results of Analyses of Dose Formulations Administered to Rats in the Perinatal and Two-year Gavage Study of Black Cohosh Root Extract

Date Prepared | Date Analyzed^a^ | Target Concentration (mg/mL) | Determined Concentration (mg/mL)^b^ | Difference from Target (%)
May 3, 2012 | May 3, 2012 | 0 | BLOQ | NA
| | 50 | 49.1 ± 0.8 | −1.9
| | 100 | 153 ± 1 | 1.8
July 26, 2012 | July 27, 2012 | 0 | BLOQ | NA
| | 15 | 15.2 ± 0.1 | 1.3
| | 50 | 50.2 ± 0.2 | 0.4
| | 150 | 153 ± 1 | 1.8
September 20, 2012 | September 20, 2012 | 0 | BLOQ | NA
| | 15 | 15.1 ± 0.1 | 0.9
| | 50 | 49.8 ± 0.2 | −0.4
| | 150 | 145 ± 1 | −3.6
December 13, 2012 | December 11, 2012 | 0 | BLOQ | NA
| | 15 | 14.7 ± 0.1 | −1.8
| | 50 | 49.5 ± 0.6 | −1.0
| | 150 | 150 ± 1 | 0.0
February 7, 2013 | February 7, 2013 | 0 | BLOQ | NA
| | 15 | 15.2 ± 0.1 | 1.1
| | 50 | 50.2 ± 0.1 | 0.4
| | 150 | 149 ± 2 | −0.4
May 2, 2013 | May 2, 2013 | 0 | BLOQ | NA
| | 15 | 15.4 ± 0.1 | 2.7
| | 50 | 51.3 ± 0.1 | 2.6
| | 150 | 152 ± 1 | 1.1
July 11, 2013 | July 11, 2013 | 0 | BLOQ | NA
| | 15 | 15.0 ± 0.1 | −0.2
| | 50 | 49.7 ± 0.1 | −0.5
| | 150 | 150 ± 1 | −0.2
September 12, 2013 | September 12, 2013 | 0 | BLOQ | NA
| | 15 | 15.1 ± 0.1 | 0.4
| | 50 | 49.0 ± 1.5 | −2.1
| | 150 | 148 ± 1 | −1.6
November 7, 2013 | November 6, 2013 | 0 | BLOQ | NA
| | 15 | 15.2 ± 0.0 | 1.3
| | 50 | 50.2 ± 0.3 | 0.4
| | 150 | 153 ± 1 | 2.0
December 19, 2013 | December 19, 2013 | 0 | BLOQ | NA
| | 15 | 14.3 ± 0.3 | −4.9
| | 50 | 50.5 ± 0.4 | 1.1
| | 150 | 146 ± 1 | −2.4
January 30, 2014 | January 31, 2014 | 0 | BLOQ | NA
| | 15 | 14.9 ± 0.2 | −0.9
| | 50 | 45.7 ± 0.4 | −8.7
| | 150 | 164 ± 2 | 9.1
April 16, 2014 | April 17, 2014 | 0 | BLOQ | NA
| | 15 | 14.3 ± 0.1 | −4.9
| | 50 | 49.3 ± 0.3 | −1.3
| | 150 | 143 ± 1 | −4.5
June 16, 2014 | June 16, 2014 | 0 | BLOQ | NA
| | 15 | 14.8 ± 0.0 | −1.3
| | 50 | 50.4 ± 0.4 | 0.8
| | 150 | 145 ± 0 | −3.3
Animal Room Samples
May 3, 2012 | June 6, 2012 | 0 | BLOQ | NA
| | 15 | 15.0 ± 0.1 | 0.0
| | 50 | 49.8 ± 0.2 | −0.3
| | 150 | 153 ± 0 | 2.0
September 20, 2012 | October 25, 2012 | 0 | BLOQ | NA
| | 15 | 15.7 ± 0.1 | 4.5
| | 50 | 53.0 ± 0.2 | 5.9
| | 150 | 155 ± 3 | 3.1
May 2, 2013 | May 28, 2013 | 0 | BLOQ | NA
| | 15 | 15.2 ± 0.0 | 1.3
| | 50 | 52.3 ± 0.3 | 4.7
| | 150 | 158 ± 1 | 5.3
| | 0 Freezer^c^ | BLOQ | NA
| | 15 Freezer^c^ | 15.4 ± 0.1 | 2.4
| | 50 Freezer^c^ | 51.7 ± 1.3 | 3.4
| | 150 Freezer^c^ | 155 ± 2 | 3.1
November 7, 2013 | December 12, 2013 | 0 | BLOQ | NA
| | 15 | 14.9 ± 0.1 | −0.9
| | 50 | 49.0 ± 0.1 | −2.1
| | 150 | 155 ± 1 | 3.1
December 19, 2013 | January 13, 2014 | 0 | BLOQ | NA
| | 15 | 14.1 ± 0.1 | −6.2
| | 50 | 51.6 ± 0.3 | 3.1
| | 150 | 152 ± 1 | 1.1
June 16, 2014 | June 30, 2014 | 0 | BLOQ | NA
| | 15 | 14.9 ± 0.0 | −0.7
| | 50 | 50.0 ± 0.1 | −0.1
| | 150 | 148 ± 2 | −1.6

BLOQ = below the limit of quantification; NA = not applicable.

^a^ Date first chromatograms were acquired.

^b^ Data are presented as mean ± standard deviation.

^c^ These samples were analyzed to determine whether storing the formulation frozen would prevent mold growth. This experiment was conducted after unidentified particles resembling mold were observed in formulations on April 13, 2013.

Table A-4 Results of Analyses of Dose Formulations Administered to Mice in the Two-year Gavage Study of Black Cohosh Root Extract

Date Prepared | Date Analyzed^a^ | Target Concentration (mg/mL) | Determined Concentration (mg/mL)^b^ | Difference from Target (%)
March 8, 2012 | March 9, 2012 | 0 | BLOQ | NA
| | 3 | 3.10 ± 0.01 | 3.3
| | 10 | 10.2 ± 0.1 | 2.3
| | 30 | 30.4 ± 0.1 | 1.3
| | 100 | 101 ± 1 | 1.3
May 3, 2012 | May 3, 2012 | 0 | BLOQ | NA
| | 3 | 2.88 ± 0.04 | −4.0
| | 10 | 10.2 ± 0.0 | 2.0
| | 30 | 29.9 ± 0.0 | −0.3
| | 100 | 92.2 ± 0.3 | −7.8
July 26, 2012 | July 27, 2012 | 0 | BLOQ | NA
| | 3 | 2.96 ± 0.01 | −1.5
| | 10 | 10.1 ± 0.0 | 1.0
| | 30 | 30.5 ± 0.0 | 1.7
| | 100 | 101 ± 0 | 1.0
September 20, 2012 | September 20, 2012 | 0 | BLOQ | NA
| | 3 | 3.00 ± 0.03 | −0.1
| | 10 | 10.1 ± 0.1 | 1.0
| | 30 | 30.3 ± 0.2 | 0.9
| | 100 | 98.8 ± 2.0 | −1.2
December 13, 2012 | December 11, 2012 | 0 | BLOQ | NA
| | 3 | 3.03 ± 0.03 | 1.0
| | 10 | 10.0 ± 0.01 | 0.0
| | 30 | 29.4 ± 0.3 | −2.0
| | 100 | 99.8 ± 0.2 | −0.2
February 7, 2013 | February 7, 2013 | 0 | BLOQ | NA
| | 3 | 3.02 ± 0.02 | 0.8
| | 10 | 10.1 ± 0.0 | 1.0
| | 30 | 30.6 ± 0.3 | 2.1
| | 100 | 100 ± 1 | 0.3
May 2, 2013 | May 2, 2013 | 0 | BLOQ | NA
| | 3 | 3.07 ± 0.02 | 2.5
| | 10 | 10.2 ± 0.1 | 2.3
| | 30 | 30.4 ± 0.1 | 1.3
| | 100 | 102 ± 1 | 2.0
July 11, 2013 | July 11, 2013 | 0 | BLOQ | NA
| | 3 | 2.92 ± 0.03 | −2.7
| | 10 | 10.0 ± 0.1 | 0.2
| | 30 | 30.1 ± 0.1 | 0.2
| | 100 | 99.7 ± 0.2 | −0.3
September 12, 2013 | September 12, 2013 | 0 | BLOQ | NA
| | 3 | 3.02 ± 0.02 | 0.8
| | 10 | 9.96 ± 0.04 | −0.4
| | 30 | 30.2 ± 0.3 | 0.6
| | 100 | 99.6 ± 0.4 | −0.4
November 7, 2013 | November 6, 2013 | 0 | BLOQ | NA
| | 3 | 2.96 ± 0.03 | −1.4
| | 10 | 10.2 ± 0.1 | 2.3
| | 30 | 30.6 ± 0.1 | 2.1
| | 100 | 97.7 ± 0.3 | −2.3
December 19, 2013 | December 19, 2013 | 0 | BLOQ | NA
| | 3 | 3.20 ± 0.02 | 6.7
| | 10 | 9.84 ± 0.02 | −1.6
| | 30 | 28.9 ± 0.2 | −3.8
| | 100 | 97.8 ± 0.2 | −2.2
January 30, 2014 | January 31, 2014 | 0 | BLOQ | NA
| | 3 | 2.74 ± 0.02 | −8.8
| | 10 | 10.1 ± 0.0 | 1.0
| | 30 | 29.0 ± 0.3 | −3.3
| | 100 | 94.1 ± 2.3 | −5.9
Animal Room Samples
March 8, 2012 | April 17, 2012 | 0 | BLOQ | NA
| | 3 | 3.09 ± 0.01 | 3.0
| | 10 | 10.2 ± 0.01 | 2.3
| | 30 | 29.8 ± 0.1 | −0.7
| | 100 | 102 ± 1 | 2.3
September 20, 2012 | October 25, 2012 | 0 | BLOQ | NA
| | 3 | 2.77 ± 0.02 | −7.6
| | 10 | 10.3 ± 0.1 | 3.3
| | 30 | 30.8 ± 0.2 | 2.6
| | 100 | 104 ± 1 | 4.0
May 2, 2013 | May 28, 2013 | 0 | BLOQ | NA
| | 3 | 3.16 ± 0.04 | 5.3
| | 10 | 10.1 ± 0.1 | 1.3
| | 30 | 30.3 ± 0.2 | 0.9
| | 100 | 102 ± 1 | 1.7
| | 0 Freezer^c^ | BLOQ | NA
| | 3 Freezer^c^ | 3.13 ± 0.02 | 4.2
| | 10 Freezer^c^ | 10.2 ± 0.0 | 2.0
| | 30 Freezer^c^ | 30.1 ± 0.2 | 0.2
| | 100 Freezer^c^ | 102 ± 1 | 2.3
November 7, 2013 | December 12, 2013 | 0 | BLOQ | NA
| | 3 | BLOQ | NA
| | 10 | 9.92 ± 0.31 | −0.8
| | 30 | 30.9 ± 0.1 | 2.9
| | 100 | 98.3 ± 1 | −1.7
| | 3 Archive^d^ | 2.91 ± 0.01 | −2.9
| | 3 Frozen^d^ | 2.85 ± 0.01 | −5.0
| | 3 Batch 37^d^ | 2.98 ± 0.03 | −0.5
December 19, 2013 | January 13, 2014 | 0 | BLOQ | NA
| | 3 Pre^e^ | 2.94 ± 0.02 | −2.0
| | 3 Post^f^ | 2.97 ± 0.00 | −1.0
| | 10 | 10.3 ± 0.1 | 2.7
| | 30 | 30.3 ± 0.0 | 1.0
| | 100 | 103 ± 1 | 2.7

BLOQ = below the limit of quantification; NA = not applicable.

^a^ Date first chromatograms were acquired.

^b^ Data are presented as mean ± standard deviation.

^c^ These samples were analyzed to determine whether storing the formulation frozen would prevent mold growth. This experiment was conducted after unidentified particles resembling mold were observed in formulations on April 13, 2013.

^d^ These samples were analyzed following receipt of the results for the November 7, 2013, batch showing BLOQ for the 3 mg/mL formulation. The “3 Archive” sample was originally collected by the chemistry group at the time of formulation preparation and stored frozen, the “3 Frozen” sample was collected by the toxicology group at the time of formulation receipt and stored frozen, and the “3 Batch 37” sample was from additional bottles of the 3 mg/mL formulation from batch 37 that were stored refrigerated.

^e^ Sample taken immediately prior to administration to animals.

^f^ Sample taken after administration to animals.

Figure A-1

Infrared Absorption Spectrum of Black Cohosh Root Extract

Figure A-2

Infrared Absorption Spectrum of Methylcellulose (Lot ZW0053)