# Overview

Tris(chloropropyl) phosphate (TCPP) is a flame retardant commonly used in consumer products. Commercial TCPP is an isomeric mixture, and variations in manufacturing methods result in commercial formulations that contain different ratios of four isomers. TCPP trade names include but are not limited to Amgard TMCP, Antiblaze 80, Antiblaze TMCP, AP 33, Fyrol PCF, and Hostaflam OP 820. The most abundant isomer in the TCPP lots used in the current studies was tris(1-chloro-2-propyl) phosphate (TCIPP; CASRN 13674-84-5; 65%–68%). Other isomers were bis(2-chloro-1-methylethyl) 2-chloropropyl phosphate (CASRN 76025-08-6; 25%–27%), bis(2-chloropropyl) 2-chloroisopropyl phosphate (CASRN 76649-15-5; 4%), and tris(2-chloropropyl) phosphate (CASRN 6145-73-9; 0.2%). The isomeric mixture of TCPP and commercial products are commonly referred to by CASRN 13674-84-5, which is the CASRN of the major isomer, TCIPP.

TCPP was nominated to the National Toxicology Program (NTP) by the U.S. Consumer Product Safety Commission (CPSC) for toxicological testing. This nomination is part of a larger effort to populate data on several flame retardants of interest (https://ntp.niehs.nih.gov/go/nm-n20608). The NTP research program on TCPP is evaluating toxicity on various cellular or molecular targets in vitro (e.g., high-throughput screening) and in vivo. TCPP effects on prenatal development in rats have been reported in NTP Developmental and Reproductive Toxicity Technical Report (DART)-01 and immunotoxicity assessments in TCPP-exposed rats are in progress. Further information on the NTP research program on TCPP is available at the Program’s website.^1^ The purpose of this report is to summarize and discuss the effects of TCPP subchronic and chronic exposure in rats and mice. Complementary research of these subchronic and chronic studies includes analysis of Tox21 (Toxicology in the 21st Century program) in vitro screening data (summary results of these data are provided in Appendix E), 5-day rat toxicogenomic study (summary results of these data are provided in Appendix F), and multiomics evaluation of hepatocellular carcinomas in mice (summary results of these data are provided in Appendix G).