# Peer Review

The National Toxicology Program (NTP) conducted a peer review of the draft NTP Technical Report on the Toxicology and Carcinogenesis Studies of an Isomeric Mixture of Tris(chloropropyl) Phosphate Administered in Feed to Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) Rats and B6C3F1/N Mice by letter in November 2022 by the experts listed below. Reviewer selection and document review followed established NTP practices. The reviewers were charged to:

1. Peer review the draft NTP Technical Report on the Toxicology and Carcinogenesis Studies of an Isomeric Mixture of Tris(chloropropyl) Phosphate Administered in Feed to Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) Rats and B6C3F1/N Mice.
2. Comment on NTP’s interpretations of the data.

NTP carefully considered reviewer comments in finalizing this report.

## Peer Reviewers

- Lois Lehman-McKeeman, Ph.D.
  Vice President
  Bristol-Myers Squibb Company, New Jersey, USA
- Richard Peterson II, D.V.M., Ph.D., DACVP
  Research Fellow and Associate Director, Pathology
  AbbVie, Illinois, USA
- Russell Cattley, V.M.D., Ph.D., DAVCP, FIATP
  Emeritus Professor and Fellow
  Auburn University and Alaplains Pathology LCC, Alabama, USA