# Collaborators

- Division of Translational Toxicology, National Institute of Environmental Health Sciences, Research Triangle Park, North Carolina, USA
  Designed studies, evaluated and interpreted results, and reported findings
  K.R. Ryan, Ph.D., Study Scientist
  A.R. Pandiri, B.V.Sc., Ph.D., Study Pathologist
  S.S. Auerbach, Ph.D.
  C.R. Blystone, Ph.D.
  M.F. Cesta, D.V.M., Ph.D.
  B.J. Collins, M.S.P.H.
  M.C. Cora, D.V.M.
  H.C. Cunny, Ph.D.
  D.R. Germolec, Ph.D.
  M.J. Hooth, Ph.D.
  J-H. Hsieh, Ph.D.
  A.P. King-Herbert, D.V.M.
  D.E. Malarkey, D.V.M., Ph.D. (Retired)
  B.S. McIntyre, Ph.D.
  S.S. Mehta, Dr.P.H.
  G.K. Roberts, Ph.D.
  K.A. Shipkowski, Ph.D.
  K.R. Shockley, Ph.D.
  S.L. Smith-Roe, Ph.D.
  M.D. Stout, Ph.D.
  G.S. Travlos, D.V.M.
  S. Waidyanatha, Ph.D.
  N.J. Walker, Ph.D.
  K.L. Witt, M.S. (Retired)
  M. Xu, Ph.D.
- Provided oversight for data management
  J.M. Fostel, Ph.D.
- Battelle, Columbus, Ohio, USA
  Conducted studies and evaluated pathology findings
  M.R. Hejtmancik, Ph.D., Principal Investigator
  B.R. Sparrow, Ph.D., Principal Investigator
  M.A. Buccellato, D.V.M., Ph.D.
  D.M. Fallacara, Ph.D.
  L.M. Fomby, D.V.M., Ph.D.
  M.J. Ryan, D.V.M., Ph.D.
  A.J. Skowronek, D.V.M., Ph.D.
  D.Y. Vasconcelos, D.V.M., Ph.D.
- Conducted prestart chemistry activities and dose formulations
  W.M. Black, B.S.
  B.L. Burback, Ph.D.
  K.A. Carrico, B.A.
  D.A. Contos, M.S.
  S.W. Graves, B.S.
  J.S. Richey, M.S.
- MRIGlobal, Kansas City, Missouri, USA
  Conducted preliminary chemistry activities, dose formulations, and biological sample chemistry analyses
  K.L. Aillon, Ph.D., Principal Investigator
  J.W. Algaier, Ph.D., Principal Investigator
  J. Cookinham, B.S.
  A. Kazerooni, M.S.
  S.P. Kerns, M.S.
  M. Kroenke, B.S.
  A.J. Mainey, B.S.
  B. O’Brien, M.S.
  D. Slade, Ph.D.
  W.R. Vandaveer, Ph.D.
- Experimental Pathology Laboratories, Inc., Research Triangle Park, North Carolina, USA
  Provided pathology review
  K.Y. Cimon, D.V.M., M.S.
  E.M. Quist, D.V.M., Ph.D.
- Coordinated Pathology Working Group on perinatal and 2-year rats (October 8, 2019) and Pathology Peer Review on uterine lesions in perinatal and 2-year rats (November 7, 2019)
  E.M. Quist, D.V.M., Ph.D.
- Coordinated Pathology Working Group on 2-year mice (October 10, 2019)
  K.Y. Cimon, D.V.M., M.S.
- Integrated Laboratory Systems, LLC, Research Triangle Park, North Carolina, USA
  Coordinated Pathology Peer Reviews on perinatal and 3-month rats and 3-month mice (May 1, 2012) and on thymus lesions in perinatal and 3-month rats (January 26, 2015)
  D.K. Giri, D.V.M., Ph.D.
- RTI International, Research Triangle Park, North Carolina, USA
  Provided sperm count and vaginal cytology evaluation (SCVCE) analysis
  R.W. Tyl, Ph.D., Principal Investigator
  C.S. Sloan, M.S.
- ICF, Fairfax, Virginia, USA
  Conducted technical writing and data integration and ensured report quality
  K.S. Duke, Ph.D.