# References

1 National Toxicology Program (NTP). Testing status of tris(Chloropropyl) phosphate (TCPP) M20263. Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Toxicology Program; 2016. https://ntp.niehs.nih.gov/go/ts-m20263
2 U.S. Environmental Protection Agency (USEPA). CompTox Chemicals Dashboard. Washington, DC: U.S. Environmental Protection Agency; 2021. https://comptox.epa.gov/dashboard
3 U.S. Environmental Protection Agency (USEPA). TSCA work plan chemical problem formulation and initial assessment: Chlorinated phosphate ester cluster flame retardants. Washington, DC: U.S. Environmental Protection Agency, Office of Chemical Safety and Pollution Prevention, Office of Pollution Prevention and Toxics; 2015. EPA Document No. EPA-740-R1-5001. https://nepis.epa.gov/Exe/ZyPURL.cgi?Dockey=P100N3WF.txt
4 U.S. Environmental Protection Agency (USEPA). Flame retardants used in flexible polyurethane foam: An alternatives assessment update. Washington, DC: U.S. Environmental Protection Agency; 2015. EPA Document No. EPA-744-R-15-002. https://nepis.epa.gov/Exe/ZyPURL.cgi?Dockey=P100MXUQ.txt
5 National Research Council (NRC). Toxicological risks of selected flame-retardant chemicals. Washington, DC: National Academies Press; 2000. https://www.ncbi.nlm.nih.gov/books/NBK225647/
6 European Union (EU). Tris(2 chloro-1 methylethyl) phosphate (TCPP), (CAS No. 13674-84-5, EINECS No. 237-158-7) risk assessment. Luxembourg: Office for Official Publications of the European Communities; 2008.
7 Agency for Toxic Substances and Disease Registry (ATSDR). Toxicological profile for phosphate ester flame retardants. Atlanta, GA: U.S. Department of Health and Human Services, Public Health Service, Agency for Toxic Substances and Disease Registry; 2012. https://www.atsdr.cdc.gov/toxprofiles/tp202.pdf
8 Wilczynski SL, Killinger JM, Zwicker GM, Freudenthal RI. Fyrol® FR-2 fertility study in male rabbits [abstract]. Toxicologist. 1983; 3(1):22.
9 World Health Organization (WHO). Flame retardants: Tris(chloropropyl) phosphate and tris(2-chloroethyl) phosphate. Geneva, Switzerland: World Health Organization; 1998. Environmental Health Criteria 209. https://apps.who.int/iris/handle/10665/42148
10 U.S. Environmental Protection Agency (USEPA). Substance Registry Service (SRS). Washington, DC: U.S. Environmental Protection Agency; 2016. https://sor.epa.gov/sor_internet/registry/substreg/LandingPage.do
11 Health Canada. Updated draft screening assessment: Certain organic flame retardants substance grouping. 2-Propanol, 1-chloro-, phosphate (3:1) (TCPP) chemical abstracts service registry number 13674-84-5, 2-propanol, 1,3-dichloro-, phosphate (3:1) (TDCPP) chemical abstracts service registry number 13674-87-8. Ottowa, ON: Environment and Climate Change Canada, Health Canada; 2020.
12 Organisation for Economic Co-operation and Development (OECD). Screening Information Dataset (SIDS) initial assessment profile: Tris(1-chloro-2-propyl)phosphate, CAS No: 13674-84-5. Geneva, Switzerland: UNEP Chemicals; 2000.
13 U.S. Environmental Protection Agency (USEPA). Reducing your child’s exposure to flame retardant chemicals. Washington, DC: U.S. Environmental Protection Agency; 2016. EPA Document No. EPA-740-16-001. https://www.epa.gov/assessing-and-managing-chemicals-under-tsca/reducing-your-childs-exposure-flame-retardant-chemicals
14 Van den Eede N, Heffernan AL, Aylward LL, Hobson P, Neels H, Mueller JF, Covaci A. Age as a determinant of phosphate flame retardant exposure of the Australian population and identification of novel urinary PFR metabolites. Environ Int. 2015; 74:1–8. 10.1016/j.envint.2014.09.005 25277340
15 Van den Eede N, Maho W, Erratico C, Neels H, Covaci A. First insights in the metabolism of phosphate flame retardants and plasticizers using human liver fractions. Toxicol Lett. 2013; 223(1):9–15. 10.1016/j.toxlet.2013.08.012 23994729
16 Estill CF, Slone J, Mayer AC, Phillips K, Lu J, Chen IC, Christianson A, Streicher R, Guardia MJ, Jayatilaka N, et al. Assessment of spray polyurethane foam worker exposure to organophosphate flame retardants through measures in air, hand wipes, and urine. J Occup Environ Hyg. 2019; 16(7):477–488. 10.1080/15459624.2019.1609004 31112485
17 Gibson EA, Stapleton HM, Calero L, Holmes D, Burke K, Martinez R, Cortes B, Nematollahi A, Evans D, Herbstman JB. Flame retardant exposure assessment: Findings from a behavioral intervention study. J Expo Sci Environ Epidemiol. 2019; 29(1):33–48. 10.1038/s41370-018-0049-6 29950671
18 Ospina M, Jayatilaka NK, Wong LY, Restrepo P, Calafat AM. Exposure to organophosphate flame retardant chemicals in the U.S. general population: Data from the 2013-2014 National Health and Nutrition Examination Survey. Environ Int. 2018; 110:32–41. 10.1016/j.envint.2017.10.001 29102155
19 Bello A, Carignan CC, Xue Y, Stapleton HM, Bello D. Exposure to organophosphate flame retardants in spray polyurethane foam applicators: Role of dermal exposure. Environ Int. 2018; 113:55–65. 10.1016/j.envint.2018.01.020 29421408
20 Hoffman K, Lorenzo A, Butt CM, Adair L, Herring AH, Stapleton HM, Daniels JL. Predictors of urinary flame retardant concentration among pregnant women. Environ Int. 2017; 98:96–101. 10.1016/j.envint.2016.10.007 27745946
21 Hammel SC, Hoffman K, Webster TF, Anderson KA, Stapleton HM. Measuring personal exposure to organophosphate flame retardants using silicone wristbands and hand wipes. Environ Sci Technol. 2016; 50(8):4483–4491. 10.1021/acs.est.6b00030 26975559
22 Kosarac I, Kubwabo C, Foster WG. Quantitative determination of nine urinary metabolites of organophosphate flame retardants using solid phase extraction and ultra performance liquid chromatography coupled to tandem mass spectrometry (UPLC-MS/MS). J Chromatogr B Analyt Technol Biomed Life Sci. 2016; 1014:24–30. 10.1016/j.jchromb.2016.01.035 26869296
23 Fromme H, Lahrz T, Kraft M, Fembacher L, Mach C, Dietrich S, Burkardt R, Völkel W, Göen T. Organophosphate flame retardants and plasticizers in the air and dust in German daycare centers and human biomonitoring in visiting children (LUPE 3). Environ Int. 2014; 71:158–163. 10.1016/j.envint.2014.06.016 25033099
24 Shi F, Liang K, Liu R, Dong Q, He Z, Xu J, Liu J. Elevated occupational exposure to chlorinated phosphate esters at a construction materials manufacturing plant. Environ Int. 2020; 139:105653. 10.1016/j.envint.2020.105653 32361061
25 Ding J, Deng T, Ye X, Covaci A, Liu J, Yang F. Urinary metabolites of organophosphate esters and implications for exposure pathways in adolescents from Eastern China. Sci Total Environ. 2019; 695:133894. 10.1016/j.scitotenv.2019.133894 31425989
26 Araki A, Bastiaensen M, Ait Bamai Y, Van den Eede N, Kawai T, Tsuboi T, Ketema RM, Covaci A, Kishi R. Associations between allergic symptoms and phosphate flame retardants in dust and their urinary metabolites among school children. Environ Int. 2018; 119:438–446. 10.1016/j.envint.2018.07.018 30031263
27 He C, Wang X, Tang S, Thai P, Li Z, Baduel C, Mueller JF. Concentrations of organophosphate esters and their specific metabolites in food in southeast Queensland, Australia: Is dietary exposure an important pathway of organophosphate esters and their metabolites? Environ Sci Technol. 2018; 52(21):12765–12773. 10.1021/acs.est.8b03043 30303374
28 Hammel SC, Stapleton HM, Eichner B, Hoffman K. Reconsidering an appropriate urinary biomarker for flame retardant tris(1-chloro-2-propyl) phosphate (TCIPP) exposure in children. Environ Sci Technol Lett. 2021; 8(1):80–85. 10.1021/acs.estlett.0c00794
29 European Chemicals Agency (ECHA). Screening report: An assessment of whether the use of TCEP, TCPP, and TCDP in articles should be restricted. Helsinki, Finland: European Chemicals Agency; 2018. https://echa.europa.eu/documents/10162/13641/screening_report_tcep_tcpp_td-cp_en.pdf/e0960aa7-f703-499c-24ff-fba627060698
30 Minegishi K, Kurebayashi H, Nambaru S, Morimoto K, Takahashi T, Yamaha T. Comparative studies on absorption, distribution, and excretion of flame retardants halogenated alkyl phosphate in rats. Eisei Kagaku. 1988; 34(2):102–114. 10.1248/jhs1956.34.102
31 National Industrial Chemicals Notification Assessment Scheme (NICNAS). Inventory Multi-tiered Assessment and Prioritisation (IMAP): 2-Propanol, 1-chloro-, 2,2',2”-phosphate: Human health tier II assessment. Sydney, Australia: Australian Government, Department of Health, National Industrial Chemicals Notification and Assessment Scheme; 2016. https://www.industrialchemicals.gov.au/sites/default/files/2-Propanol%2C%201-chloro-%2C%202%2C2%27%2C2%27%27-phosphate_Human%20health%20tier%20II%20assessment.pdf
32 National Academies of Sciences Engineering and Medicine (NASEM). A class approach to hazard assessment of organohalogen flame retardants. Washington, DC: National Academies Press; 2019. https://nap.nationalacademies.org/catalog/25412/a-class-approach-to-hazard-assessment-of-organohalogen-flame-retardants
33 Freudenthal RI, Henrich RT. A subchronic toxicity study of Fyrol PCF in Sprague-Dawley rats. Int J Toxicol. 1999; 18(3):173–176. 10.1080/109158199225468
34 Kawasaki H, Murai T, Kanoh S. Studies on the toxicity of insecticides and food additives in pregnant rats. V. Fetal toxicity of tris-(chloropropyl) phosphate (TCPP) [In Japanese]. Oyo Yakuri. 1982; 24:697–702.
35 National Toxicology Program (NTP). Developmental and reproductive toxicity technical report on the prenatal development studies of tris(chloropropyl) phosphate (CASRN 13674-84-5) in Sprague Dawley (Hsd:Sprague Dawley® SD®) rats (gavage studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Toxicology Program; 2020. NTP DART No. 1. https://ntp.niehs.nih.gov/go/dart01abs
36 Dishaw LV, Macaulay LJ, Roberts SC, Stapleton HM. Exposures, mechanisms, and impacts of endocrine-active flame retardants. Curr Opin Pharmacol. 2014; 19:125–133. 10.1016/j.coph.2014.09.018 25306433
37 Du Z, Wang G, Gao S, Wang Z. Aryl organophosphate flame retardants induced cardiotoxicity during zebrafish embryogenesis: By disturbing expression of the transcriptional regulators. Aquat Toxicol. 2015; 161:25–32. 10.1016/j.aquatox.2015.01.027 25661707
38 McGee SP, Cooper EM, Stapleton HM, Volz DC. Early zebrafish embryogenesis is susceptible to developmental TDCPP exposure. Environ Health Perspect. 2012; 120(11):1585–1591. 10.1289/ehp.1205316 23017583
39 Noyes PD, Haggard DE, Gonnerman GD, Tanguay RL. Advanced morphological - behavioral test platform reveals neurodevelopmental defects in embryonic zebrafish exposed to comprehensive suite of halogenated and organophosphate flame retardants. Toxicol Sci. 2015; 145(1):177–195. 10.1093/toxsci/kfv044 25711236
40 Meeker JD, Stapleton HM. House dust concentrations of organophosphate flame retardants in relation to hormone levels and semen quality parameters. Environ Health Perspect. 2010; 118(3):318–323. 10.1289/ehp.0901332 20194068
41 Ingle ME, Mínguez-Alarcón L, Carignan CC, Butt CM, Stapleton HM, Williams PL, Ford JB, Hauser R, Meeker JD. The association between urinary concentrations of phosphorous-containing flame retardant metabolites and semen parameters among men from a fertility clinic. Int J Hyg Environ Health. 2018; 221(5):809–815. 10.1016/j.ijheh.2018.05.001 29739653
42 Carignan CC, Mínguez-Alarcón L, Butt CM, Williams PL, Meeker JD, Stapleton HM, Toth TL, Ford JB, Hauser R, EARTH Study Team. Urinary concentrations of organophosphate flame retardant metabolites and pregnancy outcomes among women undergoing in vitro fertilization. Environ Health Perspect. 2017; 125(8):087018. 10.1289/EHP1021 28858831
43 Hoffman K, Stapleton HM, Lorenzo A, Butt CM, Adair L, Herring AH, Daniels JL. Prenatal exposure to organophosphates and associations with birthweight and gestational length. Environ Int. 2018; 116:248–254. 10.1016/j.envint.2018.04.016 29698901
44 Doherty BT, Hoffman K, Keil AP, Engel SM, Stapleton HM, Goldman BD, Olshan AF, Daniels JL. Prenatal exposure to organophosphate esters and behavioral development in young children in the Pregnancy, Infection, and Nutrition Study. Neurotoxicology. 2019; 73:150–160. 10.1016/j.neuro.2019.03.007 30951742
45 Health Canada. Screening assessment for the challenge: Ethanol, 2-chloro-, phosphate (3:1) (tris(2-chloroethyl) phosphate [TCEP]) chemical abstracts service registry number 115-96-8. Environment Canada, Health Canada; 2009.
46 Deziel NC, Yi H, Stapleton HM, Huang H, Zhao N, Zhang Y. A case-control study of exposure to organophosphate flame retardants and risk of thyroid cancer in women. BMC Cancer. 2018; 18(1):637. 10.1186/s12885-018-4553-9 29871608
47 Hoffman K, Lorenzo A, Butt CM, Hammel SC, Henderson BB, Roman SA, Scheri RP, Stapleton HM, Sosa JA. Exposure to flame retardant chemicals and occurrence and severity of papillary thyroid cancer: A case-control study. Environ Int. 2017; 107:235–242. 10.1016/j.envint.2017.06.021 28772138
48 Föllmann W, Wober J. Investigation of cytotoxic, genotoxic, mutagenic, and estrogenic effects of the flame retardants tris-(2-chloroethyl)-phosphate (TCEP) and tris-(2-chloropropyl)-phosphate (TCPP) in vitro. Toxicol Lett. 2006; 161(2):124–134. 10.1016/j.toxlet.2005.08.008 16154716
49 Nakamura A, Tateno N, Kojima S, Kaniwa MA, Kawamura T. The mutagenicity of halogenated alkanols and their phosphoric acid esters for Salmonella typhimurium. Mutat Res. 1979; 66(4):373–380. 10.1016/0165-1218(79)90048-X 379633
50 Zeiger E, Anderson B, Haworth S, Lawlor T, Mortelmans K. Salmonella mutagenicity tests: V. Results from the testing of 311 chemicals. Environ Mol Mutagen. 1992; 19 Suppl 21:2–141. 10.1002/em.2850190603 1541260
51 Williams GM, Mori H, McQueen CA. Structure-activity relationships in the rat hepatocyte DNA-repair test for 300 chemicals. Mutat Res. 1989; 221(3):263–286. 10.1016/0165-1110(89)90039-0 2682231
52 National Toxicology Program (NTP). Nomination of FR chemicals for NTP testing. Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 2005. https://ntp.niehs.nih.gov/ntp/htdocs/chem_background/exsumpdf/cpscfrsnomination_supp_062_508.pdf
53 Maronpot RR, Boorman GA. Interpretation of rodent hepatocellular proliferative alterations and hepatocellular tumors in chemical safety assessment. Toxicol Pathol. 1982; 10(2):71–78. 10.1177/019262338201000210 28094716
54 Boorman GA, Haseman JK, Waters MD, Hardisty JF, Sills RC. Quality review procedures necessary for rodent pathology databases and toxicogenomic studies: The National Toxicology Program experience. Toxicol Pathol. 2002; 30(1):88–92. 10.1080/01926230252824752 11890481
55 Brix AE, Hardisty JF, McConnell EE. Combining neoplasms for evaluation of rodent carcinogenesis studies. In: Hsu CH, Stedeford T, editors. Cancer Risk Assessment: Chemical Carcinogenesis, Hazard Evaluation, and Risk Quantification. Hoboken, NJ: Wiley; 2010. p. 699–715. 10.1002/9780470622728.ch28
56 Collins B, Slade D, Aillon K, Stout M, Betz L, Waidyanatha S, Ryan K. Plasma concentrations of tris(1-chloro-2-propyl) phosphate and a metabolite bis(2-chloroisopropyl) 1-carboxyethyl phosphate in Sprague-Dawley rats and B6C3F1/N mice from a chronic study of tris(chloropropyl) phosphate via feed. Toxicol Rep. 2022; 9:690–698. 10.1016/j.toxrep.2022.03.025 35433273
57 Kaplan EL, Meier P. Nonparametric estimation from incomplete observations. J Am Stat Assoc. 1958; 53(282):457–481. 10.1080/01621459.1958.10501452
58 Tarone RE. Tests for trend in life table analysis. Biometrika. 1975; 62(3):679–690. 10.1093/biomet/62.3.679
59 Cox DR. Regression models and life‐tables. J R Stat Soc Series B Stat Methodol. 1972; 34(2):187–202.
60 Bailer AJ, Portier CJ. Effects of treatment-induced mortality and tumor-induced mortality on tests for carcinogenicity in small samples. Biometrics. 1988; 44(2):417–431. 10.2307/2531856 3390507
61 Piegorsch WW, Bailer AJ. Statistics for environmental biology and toxicology: Section 6.3.2. London, UK: Chapman and Hall; 1997.
62 Portier CJ, Bailer AJ. Testing for increased carcinogenicity using a survival-adjusted quantal response test. Fundam Appl Toxicol. 1989; 12(4):731–737. 10.1016/0272-0590(89)90004-3 2744275
63 Portier CJ, Hedges JC, Hoel DG. Age-specific models of mortality and tumor onset for historical control animals in the National Toxicology Program’s carcinogenicity experiments. Cancer Res. 1986; 46(9):4372–4378. 3731095
64 Bieler GS, Williams RL. Ratio estimates, the delta method, and quantal response tests for increased carcinogenicity. Biometrics. 1993; 49(3):793–801. 10.2307/2532200 8241374
65 Nam JM. A simple approximation for calculating sample sizes for detecting linear trend in proportions. Biometrics. 1987; 43(3):701–705. 10.2307/2532006 3663825
66 Rao JNK, Scott AJ. A simple method for the analysis of clustered binary data. Biometrics. 1992; 48(2):577–585. 10.2307/2532311 1637980
67 Fung KY, Krewski D, Rao JNK, Scott AJ. Tests for trend in developmental toxicity experiments with correlated binary data. Risk Anal. 1994; 14(4):639–648. 10.1111/j.1539-6924.1994.tb00277.x 7972964
68 Gart JJ, Chu KC, Tarone RE. Statistical issues in interpretation of chronic bioassay tests for carcinogenicity. J Natl Cancer Inst. 1979; 62(4):957–974.10.1093/jnci/62.4.957 285297
69 Dixon WJ, Massey FJ. Introduction to statistical analysis. 2nd ed. New York, NY: McGraw Hill; 1957.
70 Tukey JW. Easy summaries--numerical and graphical. In: Exploratory Data Analysis. Reading, MA: Addison-Wesley; 1977. p. 27–56.
71 Dunnett CW. A multiple comparison procedure for comparing several treatments with a control. J Am Stat Assoc. 1955; 50(272):1096–1121. 10.1080/01621459.1955.10501294
72 Williams DA. A test for differences between treatment means when several dose levels are compared with a zero dose control. Biometrics. 1971; 27(1):103–117. 10.2307/2528930 5547548
73 Williams DA. The comparison of several dose levels with a zero dose control. Biometrics. 1972; 28(2):519–531. 10.2307/2556164 5037867
74 Shirley E. A non-parametric equivalent of Williams’ test for contrasting increasing dose levels of a treatment. Biometrics. 1977; 33(2):386–389. 10.2307/2529789 884197
75 Williams DA. A note on Shirley’s nonparametric test for comparing several dose levels with a zero-dose control. Biometrics. 1986; 42(1):183–186. 10.2307/2531254 3719054
76 Dunn OJ. Multiple comparisons using rank sums. Technometrics. 1964; 6(3):241–252. 10.1080/00401706.1964.10490181
77 Jonckheere AR. A distribution-free k-sample test against ordered alternatives. Biometrika. 1954; 41(1-2):133–145. 10.1093/biomet/41.1-2.133
78 Datta S, Satten GA. Rank-sum tests for clustered data. J Am Stat Assoc. 2005; 100(471):908–915. 10.1198/016214504000001583
79 Hommel G. A stagewise rejective multiple test procedure based on a modified Bonferroni test. Biometrika. 1988; 75(2):383–386. 10.1093/biomet/75.2.383
80 Hsu JC. The factor analytic approach to simultaneous inference in the general linear model. J Comput Graph Stat. 1992; 1(2):151–168. 10.1080/10618600.1992.10477011
81 Haseman JK. Value of historical controls in the interpretation of rodent tumor data. Drug Inf J. 1992; 26(2):191–200. 10.1177/009286159202600210
82 Haseman JK. Data analysis: Statistical analysis and use of historical control data. Regul Toxicol Pharmacol. 1995; 21(1):52–59, discussion 81–86. 10.1006/rtph.1995.1009 7784636
83 Haseman JK, Rao GN. Effects of corn oil, time-related changes, and inter-laboratory variability on tumor occurrence in control Fischer 344 (F344/N) rats. Toxicol Pathol. 1992; 20(1):52–60. 10.1177/019262339202000107 1411131
84 U.S. Food and Drug Administration (FDA). 21 CFR Part 58. https://www.accessdata.fda.gov/scripts/cdrh/cfdocs/cfcfr/CFRSearch.cfm?CFRPart=58
85 Miller JA, Miller EC. Ultimate chemical carcinogens as reactive mutagenic electrophiles. In: Hiatt HH, Watson JD, Winsten JA, editors. Origins of Human Cancer. Cold Spring Harbor, NY: Cold Spring Harbor Laboratory; 1977. p. 605–627.
86 Crawford BD. Perspectives on the somatic mutation model of carcinogenesis. In: Flamm WG, Lorentzen RJ, editors. Mechanisms and Toxicity of Chemical Carcinogens and Mutagens. Princeton, NJ: Princeton Scientific Publishing; 1985. p. 13–59.
87 Straus DS. Somatic mutation, cellular differentiation, and cancer causation. J Natl Cancer Inst. 1981; 67(2):233–241. 10.1093/jnci/67.2.233 7021938
88 Ashby J, Tennant RW. Definitive relationships among chemical structure, carcinogenicity and mutagenicity for 301 chemicals tested by the U.S. NTP. Mutat Res. 1991; 257(3):229–306. 10.1016/0165-1110(91)90003-E 1707500
89 Tennant RW, Margolin BH, Shelby MD, Zeiger E, Haseman JK, Spalding J, Caspary W, Resnick M, Stasiewicz S, Anderson B, et al. Prediction of chemical carcinogenicity in rodents from in vitro genetic toxicity assays. Science. 1987; 236(4804):933–941. 10.1126/science.3554512 3554512
90 Zeiger E, Haseman JK, Shelby MD, Margolin BH, Tennant RW, Holden HE. Evaluation of four in vitro genetic toxicity tests for predicting rodent carcinogenicity: Confirmation of earlier results with 41 additional chemicals. Environ Mol Mutagen. 1990; 16 Suppl 18:1–14. 10.1002/em.2850160502 2091921
91 Heddle JA, Hite M, Kirkhart B, Mavournin K, MacGregor JT, Newell GW, Salamone MF. The induction of micronuclei as a measure of genotoxicity: A report of the U.S. Environmental Protection Agency Gene-Tox Program. Mutat Res. 1983; 123(1):61–118. 10.1016/0165-1110(83)90047-7 6888413
92 Schmid W. The micronucleus test. Mutat Res. 1975; 31(1):9–15. 10.1016/0165-1161(75)90058-8 48190
93 Shelby MD, Erexson GL, Hook GJ, Tice RR. Evaluation of a three-exposure mouse bone marrow micronucleus protocol: Results with 49 chemicals. Environ Mol Mutagen. 1993; 21(2):160–179. 10.1002/em.2850210210 8444144
94 Shelby MD, Witt KL. Comparison of results from mouse bone marrow chromosome aberration and micronucleus tests. Environ Mol Mutagen. 1995; 25(4):302–313. 10.1002/em.2850250407 7607185
95 Witt KL, Knapton A, Wehr CM, Hook GJ, Mirsalis J, Shelby MD, MacGregor JT. Micronucleated erythrocyte frequency in peripheral blood of B6C3F(1) mice from short-term, prechronic, and chronic studies of the NTP carcinogenesis bioassay program. Environ Mol Mutagen. 2000; 36(3):163–194. 10.1002/1098-2280(2000)36:3<163::AID-EM1>3.0.CO;2-P 11044899
96 National Toxicology Program (NTP). TR-602: Pathology tables, survival and growth curves from NTP short-term, long-term, genetic toxicology, and other information studies. Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Toxicology Program; 2020. 10.22427/NTP-DATA-TR-602
97 Everds NE, Snyder PW, Bailey KL, Bolon B, Creasy DM, Foley GL, Rosol TJ, Sellers T. Interpreting stress responses during routine toxicity studies: A review of the biology, impact, and assessment. Toxicol Pathol. 2013; 41(4):560–614. 10.1177/0192623312466452 23475558
98 Marklund A, Andersson B, Haglund P. Screening of organophosphorus compounds and their distribution in various indoor environments. Chemosphere. 2003; 53(9):1137–1146. 10.1016/S0045-6535(03)00666-0 14512118
99 California Environmental Protection Agency (CalEPA). Chemicals known to the state to cause cancer or reproductive toxicity, December 29, 2017 (Proposition 65 list). Sacramento, CA: Office of Environmental Health Hazard Assessment; 2017. https://oehha.ca.gov/proposition-65/proposition-65-list
100 National Toxicology Program (NTP). Toxicology and carcinogenesis studies of tris(2-chloroethyl) phosphate (CAS No. 115-96-8) in F344/N rats and B6C3F1 mice (gavage studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 1991. NTP Technical Report No. 391. https://ntp.niehs.nih.gov/go/tr391abs
101 Dishaw LV, Powers CM, Ryde IT, Roberts SC, Seidler FJ, Slotkin TA, Stapleton HM. Is the PentaBDE replacement, tris (1,3-dichloro-2-propyl) phosphate (TDCPP), a developmental neurotoxicant? Studies in PC12 cells. Toxicol Appl Pharmacol. 2011; 256(3):281–289. 10.1016/j.taap.2011.01.005 21255595
102 Hou R, Xu Y, Wang Z. Review of OPFRs in animals and humans: Absorption, bioaccumulation, metabolism, and internal exposure research. Chemosphere. 2016; 153:78–90. 10.1016/j.chemosphere.2016.03.003 27010170
103 Wang X, Zhu Q, Yan X, Wang Y, Liao C, Jiang G. A review of organophosphate flame retardants and plasticizers in the environment: Analysis, occurrence and risk assessment. Sci Total Environ. 2020; 731:139071. 10.1016/j.scitotenv.2020.139071 32438088
104 Hall RL. Clinical pathology of laboratory animals . In: Gad SC, editor. Animal Models in Toxicology. 2nd ed. Boca Raton, FL: Taylor & Francis; 2007. p. 787–830.
105 Waner T, Nyska A. The influence of fasting on blood glucose, triglycerides, cholesterol, and alkaline phosphatase in rats. Vet Clin Pathol. 1994; 23(3):78–80. 10.1111/j.1939-165X.1994.tb00683.x 12666020
106 Gwinn WM, Auerbach SS, Parham F, Stout MD, Waidyanatha S, Mutlu E, Collins B, Paules RS, Merrick BA, Ferguson S, et al. Evaluation of 5-day in vivo rat liver and kidney with high-throughput transcriptomics for estimating benchmark doses of apical outcomes. Toxicol Sci. 2020; 176(2):343–354. 10.1093/toxsci/kfaa081 32492150
107 Quaglino D, Capri M, Bergamini G, Euclidi E, Zecca L, Franceschi C, Ronchetti IP. Age-dependent remodeling of rat thymus. Morphological and cytofluorimetric analysis from birth up to one year of age. Eur J Cell Biol. 1998; 76(2):156–166. 10.1016/S0171-9335(98)80029-0 9696356
108 Ji C, Lu Z, Xu L, Li F, Cong M, Shan X, Wu H. Global responses to tris(1-chloro-2-propyl)phosphate (TCPP) in rockfish Sebastes schlegeli using integrated proteomic and metabolomic approach. Sci Total Environ. 2020; 724:138307. 10.1016/j.scitotenv.2020.138307 32272412
109 Porter E, Crump D, Egloff C, Chiu S, Kennedy SW. Use of an avian hepatocyte assay and the avian Toxchip Polymerse chain reaction array for testing prioritization of 16 organic flame retardants. Environ Toxicol Chem. 2014; 33(3):573–582. 10.1002/etc.2469 24273086
110 Farhat A, Crump D, Chiu S, Williams KL, Letcher RJ, Gauthier LT, Kennedy SW. In ovo effects of two organophosphate flame retardants—TCPP and TDCPP—on pipping success, development, mRNA expression, and thyroid hormone levels in chicken embryos. Toxicol Sci. 2013; 134(1):92–102. 10.1093/toxsci/kft100 23629516
111 National Toxicology Program (NTP). Historical controls. Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Toxicology Program; 2021. https://ntp.niehs.nih.gov/data/controls/index.html
112 van der Veen I, de Boer J. Phosphorus flame retardants: Properties, production, environmental occurrence, toxicity and analysis. Chemosphere. 2012; 88(10):1119–1153. 10.1016/j.chemosphere.2012.03.067 22537891
113 Consumer Product Safety Commission (CPSC). Guidance document on hazardous additive, non-polymeric organohalogen flame retardants in certain consumer products. Fed Regist. 2017; 82(Sep 28):45268–45269.
114 National Institute of Standards and Technology (NIST). NIST/EPA/NIH mass spectral library (NIST 08) and NIST mass spectral search program (version 2.0d). Gaithersburg, MD: U.S. Department of Commerce, National Institute of Standards and Technology; 2008.
115 Witt KL, Livanos E, Kissling GE, Torous DK, Caspary W, Tice RR, Recio L. Comparison of flow cytometry- and microscopy-based methods for measuring micronucleated reticulocyte frequencies in rodents treated with nongenotoxic and genotoxic chemicals. Mutat Res. 2008; 649(1-2):101–113. 10.1016/j.mrgentox.2007.08.004 17869571
116 Dertinger SD, Camphausen K, MacGregor JT, Bishop ME, Torous DK, Avlasevich S, Cairns S, Tometsko CR, Menard C, Muanza T, et al. Three‐color labeling method for flow cytometric measurement of cytogenetic damage in rodent and human blood. Environ Mol Mutagen. 2004; 44(5):427–435. 10.1002/em.20075 15517570
117 Kissling GE, Dertinger SD, Hayashi M, MacGregor JT. Sensitivity of the erythrocyte micronucleus assay: Dependence on number of cells scored and inter-animal variability. Mutat Res. 2007; 634(1-2):235–240. 10.1016/j.mrgentox.2007.07.010 17851117
118 Hsieh JH, Sedykh A, Huang R, Xia M, Tice RR. A data analysis pipeline accounting for artifacts in Tox21 quantitative high-throughput screening assays. J Biomol Screen. 2015; 20(7):887–897. 10.1177/1087057115581317 25904095
119 Sedykh A. CurveP method for rendering high-throughput screening dose-response data into digital fingerprints . In: Zhu H, Xia M, editors. High-Throughput Screening Assays in Toxicology. 2016/08. 16th ed. New York, NY: Humana Press; 2016. p. 135–141. 10.1007/978-1-4939-6346-1_14
120 Hubbard TD, Hsieh JH, Rider CV, Sipes NS, Sedykh A, Collins BJ, Auerbach SS, Xia M, Huang R, Walker NJ, et al. Using Tox21 high-throughput screening assays for the evaluation of botanical and dietary supplements. Appl In Vitro Toxicol. 2019; 5(1):10–25. 10.1089/aivt.2018.0020 30944845
121 Judson RS, Thomas RS, Baker N, Simha A, Howey XM, Marable C, Kleinstreuer NC, Houck KA. Workflow for defining reference chemicals for assessing performance of in vitro assays. ALTEX. 2019; 36(2):261–276. 10.14573/altex.1809281 30570668
122 Mav D, Shah RR, Howard BE, Auerbach SS, Bushel PR, Collins JB, Gerhold DL, Judson RS, Karmaus AL, Maull EA, et al. A hybrid gene selection approach to create the S1500+ targeted gene sets for use in high-throughput transcriptomics. PLoS One. 2018; 13(2):e0191105. 10.1371/journal.pone.0191105 29462216
123 Sciome. GeniE. Research Triangle Park, NC: Sciome; 2021. https://www.sciome.com/genie/
124 National Toxicology Program (NTP). DrugMatrix/ToxFX. Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Toxicology Program; 2019. https://ntp.niehs.nih.gov/data/drugmatrix/
125 Illumina. BaseSpace Correlation Engine. 2021. https://www.illumina.com/products/by-type/informatics-products/basespace-correlation-engine.html
126 Zgheib E, Limonciel A, Jiang X, Wilmes A, Wink S, van de Water B, Kopp-Schneider A, Bois FY, Jennings P. Investigation of Nrf2, AhR and ATF4 activation in toxicogenomic databases. Front Genet. 2018; 9:429. 10.3389/fgene.2018.00429 30333853
127 Wang C, Gong B, Bushel PR, Thierry-Mieg J, Thierry-Mieg D, Xu J, Fang H, Hong H, Shen J, Su Z, et al. The concordance between RNA-seq and microarray data depends on chemical treatment and transcript abundance. Nat Biotechnol. 2014; 32(9):926–932. 10.1038/nbt.3001 25150839
128 Podtelezhnikov AA, Monroe JJ, Aslamkhan AG, Pearson K, Qin C, Tamburino AM, Loboda AP, Glaab WE, Sistare FD, Tanis KQ. Quantitative transcriptional biomarkers of xenobiotic receptor activation in rat liver for the early assessment of drug safety liabilities. Toxicol Sci. 2020; 175(1):98–112. 10.1093/toxsci/kfaa026 32119089
129 Oshida K, Vasani N, Jones C, Moore T, Hester S, Nesnow S, Auerbach S, Geter DR, Aleksunes LM, Thomas RS, et al. Identification of chemical modulators of the constitutive activated receptor (CAR) in a gene expression compendium. Nucl Recept Signal. 2015; 13(1). 10.1621/nrs.13002 25949234
130 Forbes KP, Kouranova E, Tinker D, Janowski K, Cortner D, McCoy A, Cui X. Creation and preliminary characterization of pregnane X receptor and constitutive androstane receptor knockout rats. Drug Metab Dispos. 2017; 45(10):1068–1076. 10.1124/dmd.117.075788 28716828
131 McMillian M, Nie A, Parker JB, Leone A, Kemmerer M, Bryant S, Herlich J, Yieh L, Bittner A, Liu X, et al. Drug-induced oxidative stress in rat liver from a toxicogenomics perspective. Toxicol Appl Pharmacol. 2005; 207(2 Suppl):171–178. 10.1016/j.taap.2005.02.031 15982685
132 Ganter B, Tugendreich S, Pearson CI, Ayanoglu E, Baumhueter S, Bostian KA, Brady L, Browne LJ, Calvin JT, Day GJ, et al. Development of a large-scale chemogenomics database to improve drug candidate selection and to understand mechanisms of chemical toxicity and action. J Biotechnol. 2005; 119(3):219–244. 10.1016/j.jbiotec.2005.03.022 16005536
133 Tonelli C, Chio IIC, Tuveson DA. Transcriptional regulation by Nrf2. Antioxid Redox Signal. 2018; 29(17):1727–1745. 10.1089/ars.2017.7342 28899199
134 Monroe JJ, Tanis KQ, Podtelezhnikov AA, Nguyen T, Machotka SV, Lynch D, Evers R, Palamanda J, Miller RR, Pippert T, et al. Application of a rat liver drug bioactivation transcriptional response assay early in drug development that informs chemically reactive metabolite formation and potential for drug-induced liver injury. Toxicol Sci. 2020; 177(1):281–299. 10.1093/toxsci/kfaa088 32559301
135 Liberzon A, Birger C, Thorvaldsdóttir H, Ghandi M, Mesirov JP, Tamayo P. The Molecular Signatures Database (MSigDB) hallmark gene set collection. Cell Syst. 2015; 1(6):417–425. 10.1016/j.cels.2015.12.004 26771021
136 Gusenleitner D, Auerbach SS, Melia T, Gómez HF, Sherr DH, Monti S. Genomic models of short-term exposure accurately predict long-term chemical carcinogenicity and identify putative mechanisms of action. PLoS One. 2014; 9(7):e102579. 10.1371/journal.pone.0102579 25058030
137 Ellinger-Ziegelbauer H, Gmuender H, Bandenburg A, Ahr HJ. Prediction of a carcinogenic potential of rat hepatocarcinogens using toxicogenomics analysis of short-term in vivo studies. Mutat Res. 2008; 637(1-2):23–39. 10.1016/j.mrfmmm.2007.06.010 17689568
138 Ellinger-Ziegelbauer H, Stuart B, Wahle B, Bomann W, Ahr HJ. Characteristic expression profiles induced by genotoxic carcinogens in rat liver. Toxicol Sci. 2004; 77(1):19–34. 10.1093/toxsci/kfh016 14600272
139 Ellinger-Ziegelbauer H, Stuart B, Wahle B, Bomann W, Ahr HJ. Comparison of the expression profiles induced by genotoxic and nongenotoxic carcinogens in rat liver. Mutat Res. 2005; 575(1-2):61–84. 10.1016/j.mrfmmm.2005.02.004 15890375
140 Hill T, Rooney J, Abedini J, El-Masri H, Wood CE, Corton JC. Gene expression thresholds derived from short-term exposures identify rat liver tumorigens. Toxicol Sci. 2020; 177(1):41–59. 10.1093/toxsci/kfaa102 32603419
141 Auerbach SS, Shah RR, Mav D, Smith CS, Walker NJ, Vallant MK, Boorman GA, Irwin RD. Predicting the hepatocarcinogenic potential of alkenylbenzene flavoring agents using toxicogenomics and machine learning. Toxicol Appl Pharmacol. 2010; 243(3):300–314. 10.1016/j.taap.2009.11.021 20004213
142 Fielden MR, Adai A, Dunn RT 2nd, Olaharski A, Searfoss G, Sina J, Aubrecht J, Boitier E, Nioi P, Auerbach S, et al. Development and evaluation of a genomic signature for the prediction and mechanistic assessment of nongenotoxic hepatocarcinogens in the rat. Toxicol Sci. 2011; 124(1):54–74. 10.1093/toxsci/kfr202 21813463
143 Uehara T, Hirode M, Ono A, Kiyosawa N, Omura K, Shimizu T, Mizukawa Y, Miyagishima T, Nagao T, Urushidani T. A toxicogenomics approach for early assessment of potential non-genotoxic hepatocarcinogenicity of chemicals in rats. Toxicology. 2008; 250(1):15–26. 10.1016/j.tox.2008.05.013 18619722
144 Yamada F, Sumida K, Uehara T, Morikawa Y, Yamada H, Urushidani T, Ohno Y. Toxicogenomics discrimination of potential hepatocarcinogenicity of non-genotoxic compounds in rat liver. J Appl Toxicol. 2013; 33(11):1284–1293. 10.1002/jat.2790 22806939
145 Te JA. AbdulHameed MDM, Wallqvist A. Systems toxicology of chemically induced liver and kidney injuries: Histopathology-associated gene co-expression modules. J Appl Toxicol. 2016; 36(9):1137–1149. 10.1002/jat.3278 26725466
146 Schyman P, Xu Z, Desai V, Wallqvist A. TOXPANEL: A gene-set analysis tool to assess liver and kidney injuries. Front Pharmacol. 2021; 12:601511. 10.3389/fphar.2021.601511 33633572
147 Glaab WE, Holder D, He YD, Bailey WJ, Gerhold DL, Beare C, Erdos Z, Lane P, Michna L, Muniappa N, et al. Universal toxicity gene signatures for early identification of drug-induced tissue injuries in rats. Toxicol Sci. 2021; 181(2):148–159. 10.1093/toxsci/kfab038 33837425
148 Huang L, Heinloth AN, Zeng ZB, Paules RS, Bushel PR. Genes related to apoptosis predict necrosis of the liver as a phenotype observed in rats exposed to a compendium of hepatotoxicants. BMC Genomics. 2008; 9:288. 10.1186/1471-2164-9-288 18558008
149 AbdulHameed MDM. Ippolito DL, Stallings JD, Wallqvist A. Mining kidney toxicogenomic data by using gene co-expression modules. BMC Genomics. 2016; 17(1):790. 10.1186/s12864-016-3143-y 27724849
150 Hoffmann D, Adler M, Vaidya VS, Rached E, Mulrane L, Gallagher WM, Callanan JJ, Gautier JC, Matheis K, Staedtler F, et al. Performance of novel kidney biomarkers in preclinical toxicity studies. Toxicol Sci. 2010; 116(1):8–22. 10.1093/toxsci/kfq029 20118187
151 Amin RP, Vickers AE, Sistare F, Thompson KL, Roman RJ, Lawton M, Kramer J, Hamadeh HK, Collins J, Grissom S, et al. Identification of putative gene based markers of renal toxicity. Environ Health Perspect. 2004; 112(4):465–479. 10.1289/ehp.6683 15033597
152 Yang J, Zhao YL, Wu ZQ, Si YL, Meng YG, Fu XB, Mu YM, Han WD. The single-macro domain protein LRP16 is an essential cofactor of androgen receptor. Endocr Relat Cancer. 2009; 16(1):139–153. 10.1677/ERC-08-0150 19022849
153 UniProt. UniProtKB - P22570 (ADRO_HUMAN). UniProt Consortium; 2022. https://www.uniprot.org/uniprot/P22570
154 UniProt. UniProtKB - P10275 (ANDR_HUMAN): Function. UniProt Consortium; 2022. https://www.uniprot.org/uniprot/P10275#function
155 UniProt. UniProtKB - Q8WWK9 (CKAP2_HUMAN). UniProt Consortium; 2022. https://www.uniprot.org/uniprot/Q8WWK9
156 Dunnick JK, Shockley KR, Pandiri AR, Kissling GE, Gerrish KE, Ton TV, Wilson RE, Brar SS, Brix AE, Waidyanatha S, et al. PBDE-47 and PBDE mixture (DE-71) toxicities and liver transcriptomic changes at PND 22 after in utero/postnatal exposure in the rat. Arch Toxicol. 2018; 92(11):3415–3433. 10.1007/s00204-018-2292-y 30206662
157 Schoonjans K, Peinado-Onsurbe J, Lefebvre AM, Heyman RA, Briggs M, Deeb S, Staels B, Auwerx J. PPARalpha and PPARgamma activators direct a distinct tissue-specific transcriptional response via a PPRE in the lipoprotein lipase gene. EMBO J. 1996; 15(19):5336–5348. 10.1002/j.1460-2075.1996.tb00918.x 8895578
158 Dong H, Gill S, Curran IH, Williams A, Kuo B, Wade MG, Yauk CL. Toxicogenomic assessment of liver responses following subchronic exposure to furan in Fischer F344 rats. Arch Toxicol. 2016; 90(6):1351–1367. 10.1007/s00204-015-1561-2 26194646
159 Forner A, Llovet JM, Bruix J. Hepatocellular carcinoma. Lancet. 2012; 379(9822):1245–1255. 10.1016/S0140-6736(11)61347-0 22353262
160 Kim Y, Sills RC, Houle CD. Overview of the molecular biology of hepatocellular neoplasms and hepatoblastomas of the mouse liver. Toxicol Pathol. 2005; 33(1):175–180. 10.1080/01926230590522130 15805069
161 Dhanasekaran R, Bandoh S, Roberts LR. Molecular pathogenesis of hepatocellular carcinoma and impact of therapeutic advances [version 1; peer review: 4 approved]. F1000Res. 2016; 5(F1000 Faculty Rev):879. 10.12688/f1000research.6946.1
162 McKenna A, Hanna M, Banks E, Sivachenko A, Cibulskis K, Kernytsky A, Garimella K, Altshuler D, Gabriel S, Daly M, et al. The Genome Analysis Toolkit: A MapReduce framework for analyzing next-generation DNA sequencing data. Genome Res. 2010; 20(9):1297–1303. 10.1101/gr.107524.110 20644199
163 Kovi RC, Bhusari S, Mav D, Shah RR, Ton TV, Hoenerhoff MJ, Sills RC, Pandiri AR. Genome-wide promoter DNA methylation profiling of hepatocellular carcinomas arising either spontaneously or due to chronic exposure to Ginkgo biloba extract (GBE) in B6C3F1/N mice. Arch Toxicol. 2019; 93(8):2219–2235. 10.1007/s00204-019-02505-7 31278416
164 National Toxicology Program (NTP). Toxicology and carcinogenesis studies of cumene (CAS No. 98-82-8) in F344/N rats and B6C3F1 mice (inhalation studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 2009. NTP Technical Report No. 542. https://ntp.niehs.nih.gov/go/tr542abs
165 National Toxicology Program (NTP). Toxicology and carcinogenesis studies of 3,3',4,4'-tetrachloroazobenzene (TCAB) [CAS No. 14047-09-7] in Harlan Sprague-Dawley rats and B6C3F1 mice (gavage studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 2010. NTP Technical Report No. 558. https://ntp.niehs.nih.gov/go/tr558abs
166 National Toxicology Program (NTP). Toxicology and carcinogenesis studies of ginkgo bilboa extract (CAS No. 90045-36-6) in F344/N rats and B6C3F1/N mice (gavage studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 2013. NTP Technical Report No. 578. https://ntp.niehs.nih.gov/go/tr578abs
167 National Toxicology Program (NTP). Toxicology studies of cobalt metal (CASRN 7440-48-4) in F344/N rats and B6C3F1/N mice and toxicology and carcinogenesis studies of cobalt metal in F344/NTac rats and B6C3F1/N mice (inhalation studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Toxicology Program; 2014. NTP Technical Report No. 581. https://ntp.niehs.nih.gov/go/tr581abs
168 National Toxicology Program (NTP). Toxicology and carcinogenesis studies of vinylidene chloride (CASRN 75-35-4) in F344/N rats and B6C3F1/N mice (inhalation studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Toxicology Program; 2015. NTP Technical Report No. 582. https://ntp.niehs.nih.gov/go/tr582abs
169 National Toxicology Program (NTP). Toxicology and carcinogenesis studies of oxazepam (CAS No. 604-75-1) in Swiss-Webster and B6C3F1 mice (feed studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 1993. NTP Technical Report No. 443. https://ntp.niehs.nih.gov/go/tr443abs
170 National Toxicology Program (NTP). NTP toxicology and carcinogenesis studies of primidone (CAS No. 125-33-7) in F344/N rats and B6C3F1 mice (feed studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 2000. NTP Technical Report No. 476. https://ntp.niehs.nih.gov/go/tr476abs
171 National Toxicology Program (NTP). Toxicology and carcinogenesis studies of anthraquinone (CAS No. 84-65-1) in F344/N rats and B6C3F1 mice (feed studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 2005. NTP Technical Report No. 494. https://ntp.niehs.nih.gov/go/tr494abs
172 National Toxicology Program (NTP). Toxicology and carcinogenesis studies of bromochloroacetic acid (CAS No. 5589-96-8) in F344/N rats and B6C3F1 mice (drinking water studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 2009. NTP Technical Report No. 549. https://ntp.niehs.nih.gov/go/tr549abs
173 National Toxicology Program (NTP). Toxicology studies of bromodichloroacetic acid (CASRN 71133-14-7) in F344/N rats and B6C3F1/N mice and toxicology and carcinogenesis studies of bromodichloroacetic acid in F344/NTac rats and B6C3F1/N mice (drinking water studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Toxicology Program; 2015. NTP Technical Report No. 583. https://ntp.niehs.nih.gov/go/tr583abs
174 National Toxicology Program (NTP). Toxicology studies of a pentabromodiphenyl ether mixture [DE-71 (technical grade)] (CASRN 32534-81-9) in F344/N rats and B6C3F1/N mice and toxicology and carcinogenesis studies of a pentabromodiphenyl ether mixture [DE-71 (technical grade)] in Wistar Han [Crl:WI(Han)] rats and B6C3F1/N mice (gavage studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Toxicology Program; 2016. NTP Technical Report No. 589. https://ntp.niehs.nih.gov/go/tr589abs
175 National Toxicology Program (NTP). Toxicology and carcinogenesis studies of p-chloro-α,α,α-trifluorotoluene (CASRN 98-56-6) in Sprague Dawley (Hsd: Sprague Dawley® SD®) rats and B6C3F1/N mice (inhalation studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Toxicology Program; 2018. NTP Technical Report No. 594. https://ntp.niehs.nih.gov/go/tr594abs
176 National Toxicology Program (NTP). Toxicology and carcinogenesis studies of di-n-butyl phthalate (CASRN 84-74-2) administered in feed to Sprague Dawley (Hsd:Sprague Dawley® SD®) rats and B6C3F1/N mice. Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Toxicology Program; 2021. NTP Technical Report No. 600. https://ntp.niehs.nih.gov/go/tr600abs
177 National Toxicology Program (NTP). Toxicology and carcinogenesis studies of an isomeric mixture of tris(chloropropyl) phosphate administered in feed to Sprague Dawley (Hsd:Sprague Dawley® SD®) rats and B6C3F1/N mice. Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Toxicology Program; 2023. NTP Technical Report No. 602. https://ntp.niehs.nih.gov/go/tr602abs
178 Li H, Durbin R. Fast and accurate short read alignment with Burrows-Wheeler transform. Bioinformatics. 2009; 25(14):1754–1760. 10.1093/bioinformatics/btp324 19451168
179 Martin M. Cutadapt removes adapter sequences from high-throughput sequencing reads. EMBnet J. 2011; 17(1):10–12. 10.14806/ej.17.1.200
180 Mudge JM, Harrow J. Creating reference gene annotation for the mouse C57BL6/J genome assembly. Mamm Genome. 2015; 26(9-10):366–378. 10.1007/s00335-015-9583-x 26187010
181 Frankish A, Diekhans M, Ferreira AM, Johnson R, Jungreis I, Loveland J, Mudge JM, Sisu C, Wright J, Armstrong J, et al. GENCODE reference annotation for the human and mouse genomes. Nucleic Acids Res. 2019; 47(D1):D766–D773. 10.1093/nar/gky955 30357393
182 GENCODE. Release M23 (GRCm38.p6). Hinxton, UK: EMBL-EBI; 2020. https://www.gencodegenes.org/mouse/release_M23.html
183 Patro R, Duggal G, Love MI, Irizarry RA, Kingsford C. Salmon provides fast and bias-aware quantification of transcript expression. Nat Methods. 2017; 14(4):417–419. 10.1038/nmeth.4197 28263959
184 Soneson C, Love MI, Robinson MD. Differential analyses for RNA-seq: Transcript-level estimates improve gene-level inferences [version 2; peer review: 2 approved]. F1000Res. 2015; 4:1521. 10.12688/f1000research.7563.2 26925227
185 Law CW, Chen Y, Shi W, Smyth GK. voom: Precision weights unlock linear model analysis tools for RNA-seq read counts. Genome Biol. 2014; 15(2):R29. 10.1186/gb-2014-15-2-r29 24485249
186 Ritchie ME, Phipson B, Wu D, Hu Y, Law CW, Shi W, Smyth GK. limma powers differential expression analyses for RNA-sequencing and microarray studies. Nucleic Acids Res. 2015; 43(7):e47. 10.1093/nar/gkv007 25605792
187 Robinson MD, McCarthy DJ, Smyth GK. edgeR: A bioconductor package for differential expression analysis of digital gene expression data. Bioinformatics. 2010; 26(1):139–140. 10.1093/bioinformatics/btp616 19910308
188 Andrews S. FastQC: A quality control tool for high throughput sequence data. 2010. https://www.bioinformatics.babraham.ac.uk/projects/fastqc
189 Smith T, Heger A, Sudbery I. UMI-tools: Modeling sequencing errors in Unique Molecular Identifiers to improve quantification accuracy. Genome Res. 2017; 27(3):491–499. 10.1101/gr.209601.116 28100584
190 Dobin A, Davis CA, Schlesinger F, Drenkow J, Zaleski C, Jha S, Batut P, Chaisson M, Gingeras TR. STAR: Ultrafast universal RNA-seq aligner. Bioinformatics. 2013; 29(1):15–21. 10.1093/bioinformatics/bts635 23104886
191 Griffiths-Jones S, Grocock RJ, van Dongen S, Bateman A, Enright AJ. miRBase: MicroRNA sequences, targets and gene nomenclature. Nucleic Acids Res. 2006; 34 Suppl 1:D140–D144. 10.1093/nar/gkj112 16381832
192 Liao Y, Smyth GK, Shi W. featureCounts: An efficient general purpose program for assigning sequence reads to genomic features. Bioinformatics. 2014; 30(7):923–930. 10.1093/bioinformatics/btt656 24227677
193 Li H, Handsaker B, Wysoker A, Fennell T, Ruan J, Homer N, Marth G, Abecasis G, Durbin R. The Sequence Alignment/Map format and SAMtools. Bioinformatics. 2009; 25(16):2078–2079. 10.1093/bioinformatics/btp352 19505943
194 Love MI, Huber W, Anders S. Moderated estimation of fold change and dispersion for RNA-seq data with DESeq2. Genome Biol. 2014; 15(12):550. 10.1186/s13059-014-0550-8 25516281
195 Blokzijl F, Janssen R, van Boxtel R, Cuppen E. MutationalPatterns: Comprehensive genome-wide analysis of mutational processes. Genome Med. 2018; 10(1):33. 10.1186/s13073-018-0539-0 29695279
196 Alexandrov LB, Stratton MR. Mutational signatures: The patterns of somatic mutations hidden in cancer genomes. Curr Opin Genet Dev. 2014; 24(100):52–60. 10.1016/j.gde.2013.11.014 24657537
197 Cingolani P, Platts A, Wang LL, Coon M, Nguyen T, Wang L, Land SJ, Lu X, Ruden DM. A program for annotating and predicting the effects of single nucleotide polymorphisms, SnpEff: SNPs in the genome of Drosophila melanogaster strain w1118; iso-2; iso-3. Fly (Austin). 2012; 6(2):80–92. 10.4161/fly.19695 22728672
198 R Core Team. R: A language and environment for statistical computing. R Foundation for Statistical Computing, Vienna, Austria. European Environment Agency; 2020. https://www.eea.europa.eu/data-and-maps/indicators/oxygen-consuming-substances-in-rivers/r-development-core-team-2006
199 Catalogue of Somatic Mutations in Cancer (COSMIC). Mutational signatures (v3.2 - March 2021): Single base substitution (SBS) signatures. 2021. https://cancer.sanger.ac.uk/signatures/sbs/
200 Hoenerhoff MJ, Pandiri AR, Snyder SA, Hong HH, Ton TV, Peddada S, Shockley K, Witt K, Chan P, Rider C, et al. Hepatocellular carcinomas in B6C3F1 mice treated with Ginkgo biloba extract for two years differ from spontaneous liver tumors in cancer gene mutations and genomic pathways. Toxicol Pathol. 2013; 41(6):826–841. 10.1177/0192623312467520 23262642
201 Aydinlik H, Nguyen TD, Moennikes O, Buchmann A, Schwarz M. Selective pressure during tumor promotion by phenobarbital leads to clonal outgrowth of beta-catenin-mutated mouse liver tumors. Oncogene. 2001; 20(53):7812–7816. 10.1038/sj.onc.1204982 11753661
202 Li J, Chanrion M, Sawey E, Wang T, Chow E, Tward A, Su Y, Xue W, Lucito R, Zender L, et al. Reciprocal interaction of Wnt and RXR-α pathways in hepatocyte development and hepatocellular carcinoma. PLoS One. 2015; 10(3):e0118480. 10.1371/journal.pone.0118480 25738607
203 Lin CY, Gustafsson JÅ. Targeting liver X receptors in cancer therapeutics. Nat Rev Cancer. 2015; 15(4):216–224. 10.1038/nrc3912 25786697
204 Rudraiah S, Zhang X, Wang L. Nuclear receptors as therapeutic targets in liver disease: Are we there yet? Annu Rev Pharmacol Toxicol. 2016; 56:605–626. 10.1146/annurev-pharmtox-010715-103209 26738480