# Conclusions

Under the conditions of these 2-year feed studies, there was some evidence of carcinogenic activity of tris(chloropropyl) phosphate (TCPP) in male Hsd:Sprague Dawley^®^ SD^®^ rats based on the increased incidence of hepatocellular adenoma or carcinoma (combined). There was some evidence of carcinogenic activity of TCPP in female Hsd:Sprague Dawley^®^ SD^®^ rats based on the increased incidence of uterine adenoma or adenocarcinoma (combined). The marginal increase in the incidence of hepatocellular adenoma in female rats may have been related to exposure.

There was some evidence of carcinogenic activity of TCPP in male B6C3F1/N mice based on the increased incidence of hepatocellular carcinoma. There was clear evidence of carcinogenic activity of TCPP in female B6C3F1/N mice based on the increased incidences of hepatocellular adenoma, hepatocellular carcinoma, and hepatocellular adenoma or carcinoma (combined).

In the 2-year studies, exposure to TCPP resulted in increased incidences of nonneoplastic lesions in the liver of male and female rats and in female mice, and in the kidney of male mice.