# Discussion

Tris(chloropropyl) phosphate (TCPP) is a high-production flame-retardant isomeric mixture used in textiles, furniture (flexible polyurethane foam), construction materials (rigid polyurethane foam), electronic products, paints, coatings, and adhesives.^98^ TCPP has been proposed as a substitute for brominated flame retardants and as a replacement for other chlorinated flame retardants, such as tris(2-chloroethyl) phosphate (TCEP) and tris(1,3-dichloro-2-propyl) phosphate (TDCPP), which have been identified as carcinogenic^32,99,100^ and which also pose developmental, reproductive, and neurotoxicity risks.^29,32,101^ Given the potential for increased use and exposure and the lack of publicly available toxicity data, the U.S. Consumer Product Safety Commission (CPSC) nominated TCPP for toxicological testing by the National Toxicology Program (NTP). The purpose of this report is to summarize any hazards associated with subchronic (3-month) and chronic (2-year) TCPP exposure in rats and mice so that others may compare and contrast toxicity profiles of TCPP exposure with other structurally similar flame retardants. For these NTP studies, a commercial TCPP product containing four isomers commonly found in other commercial mixtures of TCPP was procured, characterized, and utilized. These four isomers included tris(1-chloro-2-propyl) phosphate (TCIPP; CASRN 13674-84-5), bis(2-chloro-1-methylethyl) 2-chloropropyl phosphate (CASRN 76025-08-6), bis(2-chloropropyl) 2-chloroisopropyl phosphate (CASRN 76649-15-5), and tris(2-chloropropyl) phosphate (CASRN 6145-73-9).

The NTP research program on TCPP studied subchronic toxicity in male and female rats and mice exposed via dosed feed for 3 months at 0, 1,250 (mice only), 2,500, 5,000, 10,000, 20,000, or 40,000 (rats only) ppm. In rats, perinatal exposure from gestation day (GD) 6 through postnatal day (PND) 21 (weaning) preceded the subchronic exposure to provide insight to TCPP toxicity following early-life exposures. Feed exposure to TCPP was chosen to mimic intermittent ingestion, which is a common exposure route for humans.^102,103^ Literature available for exposure concentration selection in rodents was primarily from industry summaries. Reports indicated that acute toxicity of TCPP was low^4^ and feed studies with adult CD Sprague Dawley rats suggested that TCPP was well tolerated at dietary concentrations of 800–20,000 ppm after 13-weeks of exposure.^4,12,33^ Given the limited knowledge of TCPP effects on rodents during perinatal exposure and that a different rat strain was to be used, the exposure concentration selection was based on the reported lowest-observed-adverse-effect levels (LOAELs) and maximal tolerated doses. The NTP research program on TCPP also included palatability studies in adult rats and mice to better estimate acceptable exposure concentrations.

In the perinatal portion of the 3-month study, pregnant rats exposed to 40,000 ppm were euthanized humanely due to overt toxicity early in gestation. TCPP exposure did not adversely affect the survival of dams exposed to ≤20,000 ppm in feed, and signs of clinical toxicity were not observed in these animals throughout gestation or lactation. Although decreases in dam mean body weight and feed consumption appear to be related to TCPP exposure concentration, the overall effects were minimal with the majority of mean values for these parameters staying within 10%–20% of control values during the perinatal phase of TCPP exposure. TCPP exposure also had no toxicologically significant effects on littering parameters, such as percent dam delivery, litter size, or sex ratio, suggesting that pregnant rats tolerated TCPP exposures in feed at concentrations ≤20,000 ppm. These outcomes are similar to an industry summary report of a two-generation reproductive study. In this experiment, F_0_ male and female Wistar rats had lower body weights and feed consumption when exposed to approximately 300 and 1,000 mg TCPP/ kg body weight/day (mg/kg/day; through feed). At these doses, no effects were observed on littering parameters or reproductive function.^4^ In the current NTP subchronic study, TCPP-exposed offspring survived through lactation with no signs of clinical toxicity in either sex. However, offspring in the 20,000 ppm TCPP group did exhibit a time-dependent decrease in body weight gain from PND 4 through PND 21. At weaning, male and female offspring weighed approximately 30% less than control animals, whereas body weights were unaffected in groups exposed to lower TCPP concentrations. After weaning, male rats in the 20,000 ppm group were euthanized moribund by study day 5 (i.e., PND 26) of the 3-month study, while the female rats in this exposure group were kept on study. This observation informed NTP’s determination that PND 21 was potentially too early for weaning of Sprague Dawley rat offspring and the subsequent decision to extend the weaning period to PND 28 for the 2-year study to reduce stress on offspring and to increase survival.

For the remainder of the 3-month study, male and female rats survived and displayed no signs of clinical toxicity. Although female rats exposed to 20,000 ppm TCPP had mean body weights approximately 30% lower than those of control rats at the beginning of the subchronic study, this gap did not persist, and mean body weights were within 12% of control animals by study termination. Lower mean body weights in this group corresponded with a similar decrease in feed consumption. Male and female rats exposed to ≤10,000 ppm TCPP had mean body weights and feed consumption similar to those of control animals throughout the subchronic exposure period.

At the end of the 3-month study, TCPP exposure resulted in various perturbations to the liver of male and female rats. Absolute and relative liver weights were significantly increased at exposure concentrations of 10,000 (males only) and 20,000 ppm TCPP (females only); however, the magnitude of the increase was small and ranged from 10% to 20% for absolute liver weights. Minimal bile duct hyperplasia was observed in the top exposure groups (≥10,000 ppm) of both sexes and similar minimal changes were also observed in the 2-year study. Finally, several liver-related serum clinical chemistry parameters (alkaline phosphatase [ALP], alanine aminotransferase [ALT], and cholesterol) were altered in an exposure concentration-related manner for both sexes. Both ALT and ALP activities were significantly decreased. The mechanism for the decreased ALT and ALP activities was unknown but may have indicated decreased hepatocellular enzyme production or release. In particular, decreases in ALT have been associated with perturbations of gluconeogenesis or administration of substances that inhibit the cofactor pyridoxal phosphate, whereas decreases in feed consumption can cause decreases in ALP (i.e., the ALP intestinal isoenzyme).^104,105^ Although these liver enzyme changes were considered biologically relevant, there is no known toxicological significance of decreases in serum liver enzyme activity and the causes of these decreases are unknown. The mild but significant increases in cholesterol concentrations suggest an alteration in lipid metabolism. The liver has been shown to be a target organ of TCPP in previous studies, including those conducted as part of the NTP research program. In the NTP study investigating the effects of TCPP on prenatal developmental toxicity in Sprague Dawley rats, dose-related increases in absolute liver weight (9%, 16%, and 26% at 162.5, 325, and 650 mg/kg/day, respectively) were measured in dams exposed to TCPP by oral gavage from GD 6 to 20.^35^ In a different NTP study focusing on transcriptomic responses to chemical exposure, male Sprague Dawley rats that were exposed to TCPP by oral gavage (18–2,000 mg/kg/day) for 5 days had significantly increased (approximately 33%) absolute and relative liver weights in a dose-related manner.^106^ The liver is also reported to be affected by TCPP exposure in various industry summary reports. For example, in the previously mentioned studies in Sprague Dawley (CD-1) rats, an increase in liver weights occurred in the absence of histopathological changes after 14 days of repeat exposure to TCPP (4,200–16,600 ppm in feed).^4,6^ In a separate study with CD Sprague Dawley rats exposed to TCPP for 13 weeks in feed, absolute and relative liver weights were significantly increased in all male (800–20,000 ppm TCPP) and female (7,500–20,000 ppm TCPP) rats. Corresponding mild periportal hepatocellular swelling was noted in some animals at 20,000 ppm; no changes in liver histopathology were seen at other concentrations.^4,12,33^

An unusual finding in the current 3-month rat study of TCPP was an exposure concentration-related increase in absolute and relative thymus weight and size of both sexes. This increase in the thymic weights in TCPP-exposed animals correlated histologically with enlarged thymic cortex and medulla in the exposed rats compared to the control animals. The process of thymus involution in rats begins soon after birth with a gradual decrease in mitoses and an increase in apoptosis.^107^ The rate of thymic involution increases as the rats become sexually mature and increased apoptosis in the thymic cortex leads to decreased thickness. Morphometry on rat thymic tissues in this study revealed that the exposed animals exhibited enlarged cortical thickness in an exposure-dependent manner compared to control animals. Surprisingly, there were no corresponding increases in the lymphocyte populations in other lymphoid organs at the end of the subchronic exposure, and there were no lesions in the lymphoid organs at the end of the 2-year exposure. Overall, these data suggest that the increased thymic weights compared to the control animals at 3 months were likely due to a delay in thymus involution rather than due to proliferation of thymic lymphocytes. These delays in thymic involution due to perinatal chemical exposures have not been reported in the literature. To learn more, a second study was initiated to investigate potential immunological consequences of perinatal exposure to TCPP.^1^

In the 3-month TCPP studies with mice, mortality and clinical signs of toxicity were not observed in males or females exposed to 1,250, 2,500, 5,000, 10,000, or 20,000 ppm TCPP. TCPP-exposed male mice gained less weight compared to the control group in an exposure concentration-related manner. Female mice also gained less weight compared to the control group, but this response was not exposure concentration dependent. By study termination, male and female mice in the 20,000 ppm TCPP group had mean body weights that were 29% (males) and 15% (females) lower than the respective control groups. Despite lower mean body weights, feed consumption remained within 10% of control animals for the duration of the study.

Similar to rats, TCPP exposure was associated with changes in the liver of mice. Absolute liver weight was significantly increased by 39% and 25% in male and female mice in the 20,000 ppm TCPP group. Relative liver weights were also significantly increased in male and female mice exposed to ≥2,500 ppm TCPP. Liver weight increases were associated with a statistically significant increase in the incidences of hepatocellular hypertrophy in male and female mice exposed to ≥5,000 ppm TCPP. As discussed earlier in this report, significantly increased absolute and relative liver weights were also noted in rats of both sexes exposed to TCPP, but no histological correlate was noted. Typically, increased liver weights with or without corresponding hepatocellular hypertrophy are considered an adaptive change due to cytochrome P450 (CYP) enzyme induction resulting from exposure to various nuclear receptor activators. TCPP appears to be a weak activator of constitutive androstane receptor (CAR), pregnane X receptor (PXR), and peroxisome proliferator-activated receptor alpha (PPARα) in various in vitro assays as well as in a 5-day rat liver toxicogenomic study (Appendix E, Appendix F). In addition, TCPP has been shown to activate CYP enzymes at the gene expression level and protein levels across several species, including the rat, chicken, and fish model systems.^106,108-110^ Repeated chronic exposures to these nuclear receptor activators may result in the progression of hypertrophy to hyperplasia and potentially to preneoplasia and neoplasia; although this progression was not observed in rats, hypertrophy was observed in mice.

Subchronic exposure to TCPP also resulted in a decrease of absolute kidney weights in an exposure concentration-dependent manner, with the mice exposed at 20,000 ppm showing significant decreases relative to the control mice with a 22% decrease for males and a 12% decrease for females. There was a positive trend for relative kidney weights in male TCPP-exposed groups, but the response was not statistically significant by pairwise comparison. A histopathological correlate to the changes in kidney weights was not observed. However, in male mice exposed to 2,500, 5,000, 10,000, or 20,000 ppm, there was a significant increase in the incidences of cytoplasmic alteration in the outer cortical renal tubular epithelium. Cytoplasmic alteration in the renal tubular epithelium of male mice is defined as the loss of cytoplasmic vacuoles (autophagic vacuoles, lysosomes); normal female renal tubular epithelium does not exhibit similar vacuoles, suggesting that it is a sexually dimorphic feature. The toxicologic significance of this lesion is not clearly understood. Further studies are needed to better understand the toxicological significance of cytoplasmic alterations in male renal tubular epithelium.

Despite some unique differences in toxicity across rats and mice, the subchronic studies suggest that the liver is the likely target of TCPP exposure. Minimal sex differences were observed in toxicological endpoints for rats and mice. Delayed thymic involution in rat offspring may have been related to perinatal exposure to TCPP; however, more studies are needed to determine the toxicological significance of this finding. Overall, these data aided in the design and selection of exposure concentrations for the chronic studies in rats and mice.

TCPP was well tolerated in rats exposed through feed for 2 years. Maternal endpoints evaluated in time-mated rats exposed to 2,500–20,000 ppm TCPP were similar to those observed in the subchronic studies. As anticipated, there were no toxicologically significant exposure concentration-related effects on maternal survival, clinical observations, or reproductive performance. Mean body weights and feed consumption by dams during the perinatal period were similar to those of the subchronic study perinatal period. For dams, mean body weights and body weight gains fluctuated during the gestation and lactational periods, but the overall change (GD 6–21 and lactation day [LD] 1–28) in TCPP-exposed groups was consistent with control animals. Likewise, the dam feed consumption and estimated chemical intake was similar among exposure groups in both the subchronic and chronic studies of TCPP. Rat offspring in the chronic study experienced a similar pattern of lower mean body weights throughout lactation (up to 31%). The extension of the weaning time from PND 21 to PND 28 for the chronic study likely prevented premature mortality of male offspring in the 20,000 ppm group. As a result, there were no toxicologically significant effects on survival, clinical observations, feed consumption, or mean body weight for either sex by the end of the 2-year exposure period.

Lower concentrations of TCPP were used in the 2-year study of mice (i.e., males = 1,250, 2,500, and 5,000 ppm and females = 2,500, 5,000, and 10,000 ppm). Survival was not affected, and there were no clinical signs of toxicity, suggesting TCPP was well tolerated at these exposure concentrations. Given the subchronic study results, mean body weights of mice were anticipated to be ≤10% lower than that of control mice following chronic exposure. This pattern held true until approximately 2–3 months on study. Subsequently, the difference in mean body weights of male and female mice exposed to TCPP grew larger over time. By study termination, male mice in the highest exposure group of 5,000 ppm TCPP weighed 18% less, on average, than the control group. Interestingly, mean body weights of females at study termination were lower than that of the control group by 13%, 26%, and 38% in the 2,500, 5,000, and 10,000 ppm TCPP-exposed groups, respectively. Although unexpected, female mice showed no signs of clinical toxicity or significant decrease in feed consumption.

Carcinogenicity was observed in the liver of male rats and male and female mice after a 2-year oral exposure to TCPP, although the magnitude of response was greater in mice compared to rats. The relationship of the marginal response in female rats to TCPP exposure was considered uncertain. Compared to B6C3F1/N mice, incidences of hepatocellular neoplasms are rare in Sprague Dawley rats.^111^ In male rats, a positive trend (p = 0.013) in the combined incidences of hepatocellular adenomas and carcinomas was observed. The incidence of these neoplasms in the exposed groups was not statistically significant by pairwise comparison to the control group, but the incidences in the 10,000 and 20,000 ppm groups did exceed the historical control ranges (in feed studies or by all routes of exposures) for these neoplasms in male rats. On the basis of the collective study data, it was determined that there was some evidence of carcinogenicity in male rats following chronic exposure to TCPP. Additionally, a statistically significant exposure concentration-related increase in the incidences of various potential preneoplastic lesions, such as hepatic foci, was observed in male rats. The neoplasm response in the liver of female rats was not as robust. Hepatocellular carcinomas were not observed in female rats, but there were slightly higher incidences of hepatocellular adenomas in the lowest and highest exposure groups and two females in the 20,000 ppm group had multiple adenomas. The adenoma increases in female rats did not reach statistical significance for either the trend or pairwise comparisons and were within historical control ranges (in feed studies or by all routes of exposures). Similar to males, there were statistically significant exposure concentration-related increases in the incidences of various potential preneoplastic lesions, such as hepatic foci, in female rats. Having compared the strength of evidence in male rats and male and female mice, it was determined that the carcinogenic response in female rat livers may have been related to exposure.

In male mice, the incidences of hepatocellular carcinomas were significantly increased by pairwise comparison to the control group in all TCPP-exposed groups, although the incidence rates in TCPP groups were within the historical control range. It is noteworthy that the incidence of hepatocellular carcinoma in control male mice in this study was at the lower end of NTP’s historical range for this neoplasm (i.e., 10%–20% for feed studies; 10%–36% by all exposure routes). These data demonstrate that TCPP elicited some evidence of carcinogenic activity in the liver of male mice following 2 years of exposure.

Female mice exhibited a positive trend in the incidences of hepatocellular adenomas, carcinomas, and adenomas or carcinomas (combined) with the incidence in the highest exposure group of 10,000 ppm significantly different from the control group by pairwise test. Additionally, the incidence of hepatocellular adenomas, carcinomas, and adenomas or carcinomas (combined) in female mice exposed to either 5,000 or 10,000 ppm was higher than historical control values in other feed studies. There was a statistically significant increase in the incidences of potential preneoplastic changes such as hepatic foci, which was not observed in male mice. This study demonstrated that TCPP had clear evidence of carcinogenic activity in female mice based on the increased incidence of liver neoplasms.

Additional neoplasms of toxicological significance were noted in female rats. A positive trend was observed in the incidences of uterine adenoma or adenocarcinoma (combined). Although the incidence for these combined neoplasms in TCPP-exposed female rats was not statistically significant by pairwise comparison to concurrent study control animals, there was an exposure-related doubling and tripling of the incidence. In addition, the combined incidence of uterine adenoma or adenocarcinoma did exceed historical control ranges by feed or all exposure routes in the 5,000, 10,000, and 20,000 ppm groups. These data suggest that TCPP contributed to the formation of rat uterine lesions in this study and represent some evidence of carcinogenic activity. Furthermore, solitary incidences of squamous cell carcinoma in the 10,000 and 20,000 ppm groups as well as the higher incidences of potential preneoplastic lesions, such as atypical endometrial hyperplasia, support the observation of the uterus being a neoplasm target organ after chronic TCPP exposure. In general, proliferative lesions in the uterus are more common in the Hsd:Sprague Dawley^®^ SD^®^ rats than in mice. Not surprisingly, the uterus was not a target organ in the mouse study. In summary, the toxicological or carcinogenic mode of action needs further mechanistic evaluation to completely understand the potential for endocrine disruption due to TCPP exposure.

The mechanisms for the observed carcinogenic response in the liver in these studies are not well understood. The findings from NTP’s bacterial mutagenicity studies and in vivo micronucleus assessments, as well as reports in the literature suggest that TCPP has little or no genotoxic potential, and therefore the development of neoplasms is likely due to a nongenotoxic mode of action. To learn more about potential mechanisms of TCPP toxicity and carcinogenicity, data were integrated from three separate investigations. First, the biological activity of TCPP measured in various Toxicology in the 21st Century (Tox21) high-throughput screening assays suggest it is a weak activator of the constitutive androstane receptor (CAR) and pregnane X receptor (PXR) compared to the prototype CAR and/or PXR activators (Appendix E). In addition, an NTP toxicogenomic study also suggests that TCPP activates several biomarker hepatic transcripts related to CAR, PXR, and peroxisome proliferator-activated receptor alpha (PPARα) signaling pathways following a 5-day exposure in rats (Appendix F). A third data stream comes from a multiomics examination of male mouse hepatocellular carcinomas arising spontaneously or following chronic exposure to TCPP (i.e., tumor analysis from this 2-year study). This investigation indicated no significant differences in the overall mutation burden in animals developing hepatocellular carcinomas spontaneously or after chronic exposure to TCPP, supporting the hypothesis that TCPP may not function through a genotoxic mode of action. The mutation signatures of mouse hepatocellular carcinomas arising spontaneously or due to chronic exposure to TCPP are comparable, but the TCPP-exposed group contained additional mutation spectra and cancer driver genes, suggesting that TCPP is likely associated with a nongenotoxic mechanism and may function as a tumor promoter (Appendix G). Future mechanistic evaluations regarding the role of specific TCPP isomers or metabolites may provide additional clarity to the tumor promotor hypothesis.

To provide additional context to the toxicological data, an assessment of internal exposure in rats and mice at 3, 6, 12, and 18 months was included in the NTP chronic study. The major isomer of TCPP, tris(1-chloro-2-propyl) phosphate (TCIPP), was quantified in plasma. The data are published in Collins et al.,^56^ and are briefly summarized here. In male and female rats exposed to 2,500–20,000 ppm TCPP, TCIPP plasma concentrations ranged from 3.43 to 78.4 ng/mL and increased with exposure concentration at all time points but was not often in proportion with exposure concentration. TCIPP concentrations were variable within and between time points for a given exposure concentration, which made it difficult to discern whether there was sex difference in rats. TCIPP concentrations in mouse plasma were somewhat higher than in rats and ranged from 6.6 to 1,180 ng/mL when exposed to 1,250–5,000 ppm (males) or 2,500–10,000 ppm (females). At a similar exposure concentration of TCPP in feed (i.e., 5,000 ppm), the estimated TCPP intake was approximately 250–800 mg/kg/day by rats versus approximately 575–1,500 mg/kg/day by mice. The estimated intake of TCPP, based on feed consumption data, may partly explain why plasma TCIPP levels were up to three times higher in mice. Moreover, higher internal exposure in mice, compared to rats, may help explain or distinguish the evidence of carcinogenicity observed in mice on this study. Similar to rats, TCIPP concentrations in mice increased with exposure concentration at all time points, but this increase was not always in proportion with exposure concentration. Sex differences were noted in mice, with males having consistently higher plasma concentrations than females. This difference may result from slightly higher feed consumption and estimated TCPP uptake in male mice compared to females. TCPP did not bioaccumulate in rats or mice over the course of the study. This finding is consistent with other reports demonstrating that TCPP and other chlorinated organophosphate flame retardants exhibit lower bioaccumulation or bioconcentration compared with other classes of flame retardants.^102,112^ It is noteworthy that low concentrations of TCIPP were observed in some rat and mouse plasma from control groups. Sample preparation and analysis were attributed as the source of these low concentrations because of the ubiquitous presence of TCPP, which was determined by measuring a metabolite of TCPP—bis(2-chloroisopropyl) 1-carboxyethyl phosphate (BCPCP) —in plasma from limited control and TCPP-exposed animals and utilizing the ratio of BCPCP:TCIPP.^56^ Overall, internal concentrations of TCIPP were estimated for comparison to TCPP exposure concentrations that were associated with an increase in the incidence of neoplasms in rats and mice.

The measurement of TCPP isomers or their metabolites in biological matrices is not often reported in a consistent manner, which complicates attempts to associate human exposure with rodent exposure levels in toxicity studies. Plasma TCIPP concentrations were not available for humans and hence using the rodent TCIPP data to provide context for human exposures is not feasible at this time. It is clear that more consistent internal exposure data are required to assess the relevance of animal toxicity data to human exposures. Because TCPP is cleared rapidly and metabolized extensively to BCPCP, BCPCP might be a more suitable biomarker of TCPP exposure for consideration in biomonitoring studies. Future studies are suggested to further characterize this possibility. Despite this limitation, these chronic toxicological assessments in rats and mice are expected to assist with several national and international efforts to evaluate the comparative toxicity of TCPP and structurally similar flame retardants TCEP and TDCPP. Organizations such as CPSC, the European Chemicals Agency, and Health Canada have published guidance for or noted their intent to restrict the use of this class of chemicals on the basis of their toxicity profiles.^11,29,32,113^