# Results

## Data Availability

All study data were evaluated. Data relevant for evaluating toxicological findings are presented here. All study data are available in the National Toxicology Program (NTP) Chemical Effects in Biological Systems (CEBS) database: https://doi.org/10.22427/NTP-DATA-TR-602.^96^

## Rats

### Three-month Study (Perinatal Phase)

Maternal toxicity was observed in dams exposed to 40,000 ppm tris(chloropropyl) phosphate (TCPP). One dam was moribund and euthanized on gestation day (GD) 11; on GD 13, all remaining 40,000 ppm dams were either found dead or euthanized moribund (data not shown). Therefore, this exposure group will not be displayed in tables for lactation or postweaning data. The mean body weight of dams in this group was approximately 20% lower than that of the control group on GD 9 and GD 12, and feed consumption was significantly decreased by 31% from GD 6 through GD 9 and was lower by 24% from GD 9 through GD 12 compared to the control group (Appendix H).

All dams in the control group and remaining TCPP-exposed groups (2,500, 5,000, 10,000, and 20,000 ppm) survived during gestation (Table 4). The percentage of dams delivering was variable across TCPP-exposed groups. There was no clear exposure concentration response, and the number of dams in each group was different, so the biological significance of this finding is unclear. Maternal survival was not affected in the control group or TCPP-exposed groups during the lactation phase (Table 5).

Table 4 Summary of the Disposition of F_0_ Female Rats during Perinatal Exposure in the Perinatal and Three-month Feed Study of Tris(chloropropyl) Phosphate

| 0 ppm | 2,500 ppm | 5,000 ppm | 10,000 ppm | 20,000 ppm
Reproductive Performance
Time-mated Females (GD 6) | 20 | 20 | 8 | 20 | 8
Females Pregnant (%)^a^ | 18 (90) | 17 (85) | 6 (75) | 17 (85) | 6 (75)
Females Not Pregnant (%) | 2 (10) | 3 (15) | 2 (25) | 3 (15) | 2 (25)
Dams Not Delivering with Evidence of Pregnancy (%)^b^ | 0 | 0 | 1 (16.7) | 1 (5.9) | 0
Dams with Litters on LD 0 (%)^a,b,c^ | 13 (100) | 13 (100) | 5 (83.3) | 11 (91.7) | 6 (100)
Litters Poststandardization (PND 4)^d^ | 6 | 7 | 5 | 5 | 6
Weaned Males/Females | 24/24 | 26/28 | 21/18 | 20/19 | 27/21

The 40,000 ppm group was euthanized due to moribund condition or found dead on GD 11 or 13.

GD = gestation day; LD = lactation day; PND = postnatal day.

^a^ Statistical analysis performed by the Cochran-Armitage (trend) and Fisher’s exact (pairwise) tests. No statistically significant findings were noted at p ≤ 0.05.

^b^ Percentage is given as a portion of pregnant dams.

^c^ Five, four, and five pregnant dams were removed from the 0, 2,500, and 10,000 ppm groups, respectively, on GD 18 for biological sample collection.

^d^ Standardization to eight pups/litter (four pups/sex).

Table 5 Summary of Mean Body Weights and Body Weight Gains of F_0_ Female Rats during Gestation and Lactation in the Perinatal and Three-month Feed Study of Tris(chloropropyl) Phosphate

Parameter^a,b^ | 0 ppm | 2,500 ppm | 5,000 ppm | 10,000 ppm | 20,000 ppm | 40,000 ppm^c^
Gestation Body Weight
Gestation Day
6 | 217.3 ± 2.3 (18) | 217.6 ± 2.90 (17) | 221.6 ± 3.0 (6) | 215.2 ± 4.4 (17) | 219.4 ± 3.4 (6) | 214. 7 ± 2.7 (20)
9 | 234.3 ± 2.0** (18) | 234.8 ± 2.5 (17) | 237.2 ± 4.7 (6) | 230.4 ± 3.2 (17) | 221.6 ± 4.5* (6) | 191. 7 ± 2.6** (20)
12 | 252.3 ± 1.9** (18) | 251.5 ± 2.8 (17) | 255.7 ± 4.7 (6) | 249.4 ± 3.3 (17) | 243.4 ± 4.2 (6) | 194.0 ± 6.0** (19)
15 | 266.8 ± 2.3 (18) | 269.6 ± 3.1 (17) | 271.4 ± 7.5 (6) | 265.6 ± 3.5 (17) | 265.1 ± 4.8 (6) | –^d^
18^e^ | 308.9 ± 3.3 (14) | 314.3 ± 3.4 (14) | 312.7 ± 11.0 (6) | 306.9 ± 7.5 (12) | 296.3 ± 10.4 (6) | –
21 | 354.6 ± 4.3 (13) | 357.2 ± 4.4 (13) | 353.3 ± 17.0 (6) | 346.4 ± 10.8 (12) | 348.2 ± 7.0 (6) | –
Gestation Weight Change
Gestation Day Interval
6–9 | 17.0 ± 1.1** (18) | 17.2 ± 1.1 (17) | 15.6 ± 3.1 (6) | 15.2 ± 1.7 (17) | 2.2 ± 2.7** (6) | −23.1 ± 3.1** (20)
9–12 | 17.9 ± 0.877* (18) | 16.7 ± 1.0 (17) | 18.4 ± 1.5 (6) | 19.1 ± 1.1 (17) | 21.8 ± 1.8 (6) | 1.4 ± 4.6** (19)
12–15 | 14.5 ± 0.8** (18) | 18.1 ± 0.9 (17) | 15.7 ± 3.2 (6) | 16.1 ± 1.1 (17) | 21.8 ± 1.1** (6) | –
15–18 | 41.0 ± 1.3 (14) | 41.9 ± 1.1 (14) | 41.4 ± 3.9 (6) | 38.7 ± 4.0 (12) | 31.2 ± 11.7 (6) | –
18–21 | 44.5 ± 1.6 (13) | 42.4 ± 1.7 (13) | 40.5 ± 6.2 (6) | 39.5 ± 3.9 (12) | 52.0 ± 6.6 (6) | –
6–21 | 133.7 ± 3.3 (13) | 138.5 ± 3.8 (13) | 131.6 ± 15.4 (6) | 126.4 ± 9.5 (12) | 128.9 ± 8.0 (6) | –
Lactation Body Weight
Lactation Day
1 | 261.0 ± 3.4 (13) | 266.7 ± 2.8 (13) | 274.3 ± 7.7 (5) | 269.6 ± 4.2 (11) | 257.3 ± 7.4 (6) | –
4 | 278.2 ± 3.5 (13) | 287.7 ± 3.4 (13) | 290.8 ± 9.7 (5) | 287.7 ± 4.0 (11) | 262.7 ± 7.8 (6) | –
7^f^ | 283.5 ± 4.2 (6) | 291.9 ± 4.3 (7) | 293.1 ± 5.1 (5) | 294.8 ± 2.7 (5) | 270.9 ± 7.6 (6) | –
14 | 267.5 ± 8.9 (6) | 274.0 ± 5.6 (7) | 274.3 ± 14.6 (5) | 268.4 ± 12.7 (5) | 257.7 ± 5.6 (6) | –
21 | 292.0 ± 2.3 (6) | 304.9 ± 6.3 (7) | 302.3 ± 6.2 (5) | 290.4 ± 8.3 (5) | 273.3 ± 11.0 (6) | –
Lactation Weight Change
Lactation Day Interval
1–4 | 17.2 ± 1.6 (13) | 21.0 ± 2.0 (13) | 16.5 ± 4.3 (5) | 18.1 ± 2.4 (11) | 5.4 ± 3.0** (6) | –
4–7 | 5.5 ± 4.1 (6) | 5.3 ± 2.6 (7) | 2.3 ± 5.1 (5) | 8.2 ± 5.2 (5) | 8.2 ± 1.5 (6) | –
7–14 | −16.0 ± 11.3 (6) | −17.9 ± 4.7 (7) | −18.8 ± 10.2 (5) | −26.4 ± 12.5 (5) | −13.2 ± 6.2 (6) | –
14–21 | 24.5 ± 9.9 (6) | 31.0 ± 8.2 (7) | 28.1 ± 8.6 (5) | 22.0 ± 9.1 (5) | 15.7 ± 7.2 (6) | –
1–21 | 35.6 ± 2.7** (6) | 37.1 ± 3.3 (7) | 28.0 ± 4.5 (5) | 25.8 ± 4.9 (5) | 16.0 ± 6.9** (6) | –

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ Each exposed group was compared to the vehicle control group with the Williams test when a trend was present (p ≤ 0.01 from the Jonckheere trend test) or with the Dunnett test when no trend was present.

^b^ Data are presented as mean ± standard error (number of dams). Body weight data are presented in grams.

^c^ Nonpregnant females were excluded from analysis for all groups except for the 40,000 ppm group. Pregnancy status was unknown for the 40,000 ppm group, so all animals from this group were included in the analysis until time of removal.

^d^ The 40,000 ppm group was euthanized due to moribund condition or found dead on GD 11 or 13.

^e^ Decreased number of dams at GD 18 reflects animals removed at GD 18 for biological sample collection.

^f^ Decreased number of litters at lactation day 7 reflects number of litters poststandardization.

Mean body weight gain and feed consumption by dams in the 20,000 ppm TCPP group fluctuated during gestation. Body weight gain was significantly decreased during GD 6–9 and then significantly increased during GD 12–15. Overall, mean body weight gain during gestation (GD 6–21) was within 10% of that of the control dams (Table 5). Likewise, dams in the 20,000 ppm group had a terminal mean body weight on lactation day (LD) 21 that was only 6% lower than that of the control group. Mean body weight gains in TCPP-exposed groups ≤10,000 ppm were largely within 10% of, and not statistically different from, the control group (Table 5). During several gestation intervals (GD 6–9, 12–15, and 15–18), feed consumption trended higher with increasing exposure concentration (Table 6). Feed consumption during GD intervals 12–15 and 6–21 was significantly increased in the 20,000 ppm TCPP group compared to the control group (Table 6). Chemical intake during gestation (GD 6 through GD 21) was estimated to be 186, 379, 802, and 1,756 mg TCPP/kg body weight/day (mg/kg/day) for the 2,500, 5,000, 10,000, and 20,000 ppm groups, respectively. In general, the estimated TCPP intake was proportional to the twofold increase in the respective TCPP exposure concentrations in feed.

Table 6 Summary of Feed and Tris(chloropropyl) Phosphate Consumption by F_0_ Female Rats during Gestation and Lactation in the Perinatal and Three-month Feed Study

Parameter^a^ | 0 ppm | 2,500 ppm | 5,000 ppm | 10,000 ppm | 20,000 ppm | 40,000 ppm^b^
Gestation Day Interval^c,d^
6–9 | 17.7 ± 0.3* (18) | 17.3 ± 0.30 (17) | 17.3 ± 1.2 (6) | 19.3 ± 1.3 (16) | 21.1 ± 2.9 (6) | 12.2 ± 1.6* (20)
9–12 | 18.1 ± 0.2 (18) | 18.2 ± 0.4 (17) | 19.6 ± 0.9 (6) | 20.2 ± 0.8 (17) | 24.3 ± 2.1 (6) | 13.8 ± 2.5 (19)
12–15 | 18.9 ± 0.3** (18) | 19.7 ± 0.4 (17) | 20.3 ± 0.8 (6) | 20.1 ± 0.5 (17) | 22.7 ± 0.9** (6) | 21.0 ± 2.6** (19)
15–18 | 21.4 ± 0.3** (18) | 21.5 ± 0.5 (17) | 22.4 ± 0.6 (6) | 22.6 ± 0.7 (17) | 23.6 ± 2.3 (6) | –^e^
18–21 | 22.8 ± 0.5 (13) | 22.2 ± 0.4 (13) | 23.4 ± 0.8 (6) | 23.1 ± 0.8 (12) | 25.3 ± 1.2 (5) | –
6–21^f^ | 19.7 ± 0.2** (13) | 20.1 ± 0.3 (13) | 20.6 ± 0.7 (6) | 21.3 ± 0.8 (12) | 22.6 ± 1.2* (5) | –
Lactation Day Interval^c,d^
1–4 | 33.4 ± 1.1 (13) | 34.5 ± 1.0 (13) | 35.6 ± 2.1 (5) | 35.2 ± 1.4 (11) | 33.6 ± 2.1 (5) | –
4–7 | 42.3 ± 1.2 (6) | 38.5 ± 1.1 (7) | 39.8 ± 1.0 (5) | 40.5 ± 0.6 (5) | 40.1 ± 3.4 (6) | –
7–10 | 47.7 ± 1.3 (6) | 45.6 ± 1.2 (7) | 48.0 ± 0.9 (5) | 45.4 ± 0.6 (5) | 45.9 ± 2.7 (6) | –
10–14 | 42.6 ± 1.5* (6) | 45.2 ± 1.4 (7) | 44.1 ± 1.5 (5) | 40.1 ± 2.7 (5) | 33.1 ± 1.8 (3) | –
14–17 | 55.1 ± 1.1 (6) | 54.1 ± 0.7 (7) | 55.5 ± 0.8 (5) | 55.5 ± 0.6 (5) | 53.5 ± 0.5 (4) | –
17–21 | 76.7 ± 3.6 (6) | 68.0 ± 1.9 (7) | 66.7 ± 1.1 (5) | 66.5 ± 2.6 (5) | 76.9 ± 6.3 (5) | –
1–14^g^ | 41.6 ± 1.1 (6) | 41.1 ± 0.3 (7) | 42.0 ± 0.5 (5) | 40.0 ± 0.9 (5) | 38.0 ± 1.1 (3) | –
Chemical Intake (mg/kg/day)^h,i^
GD 6–21^f^ | 0.00 ± 0.00 (13) | 185.7 ± 2.7 (13) | 379.1 ± 8.5 (6) | 801.7 ± 27.9 (12) | 1,756 ± 87.9 (5) | –
LD 1–14^g^ | 0.00 ± 0.00 (6) | 365.5 ± 7.0 (7) | 743.1 ± 22.6 (5) | 1,430 ± 52.6 (5) | 2,974 ± 104.7 (3) | –

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

GD = gestation day; LD = lactation day.

^a^ Data are presented as mean ± standard error (number of dams).

^b^ Nonpregnant females were excluded from analysis for all groups except for the 40,000 ppm group. Pregnancy status was unknown for the 40,000 ppm group, so all animals from this group were included in the analysis until time of removal.

^c^ Feed consumption data are presented as grams/animal/day.

^d^ Each exposed group was compared to the vehicle control group with the Shirley test when a trend was present (p ≤ 0.01 from the Jonckheere trend test) or with the Dunn test when no trend was present.

^e^ The 40,000 ppm group was euthanized due to moribund condition or found dead on GD 11 or 13.

^f^ Dams missing a value for any of the separate time intervals of GD 6 through GD 21 were excluded from the GD 6–21 endpoint.

^g^ Dams missing a value for any of the separate time intervals of LD 1 through LD 14 were excluded from the LD 1–14 endpoint.

^h^ Chemical intake calculated as: ([exposure concentration × feed consumption]/[average body weight of day range]).

^i^ No statistical analysis performed on the chemical intake data.

There were no significant differences in mean body weight of TCPP-exposed dams compared to control animals during lactation, with values within 10% of those of the control group. However, maternal body weight gain was significantly decreased in the 20,000 ppm TCPP group over the course of lactation (LD 1 through LD 21); weight gains by dams exposed to ≤10,000 ppm TCPP were similar to the control group despite the fact that values fluctuated over time (Table 5). Feed consumption during lactation also sporadically changed over time with the greatest decrease (compared to control animals) of 22% in the 20,000 ppm group over the LD 10–14 interval (Table 6). Chemical intake during LD 1–14 was estimated to be 366, 743, 1,430, and 2,974 mg/kg/day for the 2,500, 5,000, 10,000, and 20,000 ppm groups, respectively. Chemical intake from LD 14 through LD 21 was not calculated because the entire litter ate the feed and an accurate assessment could not be made. Overall, the estimated TCPP intake was proportional to the twofold increase in the respective TCPP exposure concentrations in feed.

At postnatal day (PND) 1, there were no effects of TCPP exposure on litter size, litter weight, or sex distribution (Table 7, Table 8). Pup survival was also not affected during lactation. Male and female pup mean body weights in the 20,000 ppm group were significantly decreased compared to those of the control groups from PND 4 through PND 21 (Table 8), which was interpreted as lower body weight gains compared to control pups. Male pup mean body weights were significantly decreased by 15%, 19%, 20%, and 31% relative to that of the control group at PNDs 4, 7, 14, and 21, respectively (Table 8). Female pup mean body weights were significantly decreased by 14%, 18%, 19%, and 27% relative to that of the control group at PNDs 4, 7, 14, and 21, respectively (Table 8).

Table 7 Summary of Mean Litter Size and Survival Ratio of F_1_ Male and Female Rats during Lactation in the Perinatal and Three-month Feed Study of Tris(chloropropyl) Phosphate

Parameter | 0 ppm | 2,500 ppm | 5,000 ppm | 10,000 ppm | 20,000 ppm
PND 1
Total^a,b^ | 12.31 ± 0.49 (13) | 12.69 ± 0.52 (13) | 13.00 ± 1.05 (5) | 12.27 ± 0.59 (11) | 13.33 ± 0.61 (6)
Live^a,b^ | 11.92 ± 0.50 (13) | 12.54 ± 0.49 (13) | 12.80 ± 0.92 (5) | 12.09 ± 0.65 (11) | 13.17 ± 0.60 (6)
% Male/Litter^a,b,c^ | 53.01 ± 3.76 (9) | 50.38 ± 4.04 (10) | 45.86 ± 0.40 (3) | 56.16 ± 5.02 (8) | 55.24 ± 7.87 (5)
% Male^d,e^ | 53 (109) | 51 (125) | 46 (37) | 56 (102) | 54 (65)
Male^a,b^
PND 1^c^ | 6.44 ± 0.63 (9) | 6.40 ± 0.67 (10) | 5.67 ± 0.67 (3) | 7.13 ± 0.61 (8) | 7.00 ± 0.71 (5)
PND 4 Prestandardization^c^ | 6.44 ± 0.63 (9) | 6.30 ± 0.68 (10) | 5.67 ± 0.67 (3) | 7.00 ± 0.63 (8) | 7.20 ± 0.80 (5)
PND 4 Poststandardization | 4.00 ± 0.00 (6) | 4.00 ± 0.00 (7) | 4.20 ± 0.20 (5) | 4.00 ± 0.00 (5) | 4.50 ± 0.34 (6)
Female^a,b^
PND 1^c^ | 5.67 ± 0.55 (9) | 6.10 ± 0.46 (10) | 6.67 ± 0.67 (3) | 5.63 ± 0.68 (8) | 6.00 ± 1.26 (5)
PND 4 Prestandardization^c^ | 5.67 ± 0.55 (9) | 6.10 ± 0.46 (10) | 6.67 ± 0.67 (3) | 5.50 ± 0.71 (8) | 5.60 ± 1.33 (5)
PND 4 Poststandardization | 4.00 ± 0.00 (6) | 4.00 ± 0.00 (7) | 3.80 ± 0.20 (5) | 4.00 ± 0.00 (5) | 3.50 ± 0.34 (6)
Male and Female^a,b^
PND 4 Prestandardization | 11.08 ± 1.05 (13) | 12.46 ± 0.49 (13) | 12.80 ± 0.92 (5) | 11.82 ± 0.70 (11) | 13.00 ± 0.63 (6)
PND 4 Poststandardization | 8.00 ± 0.00 (6) | 8.00 ± 0.00 (7) | 8.00 ± 0.00 (5) | 8.00 ± 0.00 (5) | 8.00 ± 0.00 (6)
PND 7 | 8.00 ± 0.00 (6) | 7.71 ± 0.18 (7) | 8.00 ± 0.00 (5) | 8.00 ± 0.00 (5) | 8.00 ± 0.00 (6)
PND 10 | 8.00 ± 0.00 (6) | 7.71 ± 0.18 (7) | 8.00 ± 0.00 (5) | 7.80 ± 0.20 (5) | 8.00 ± 0.00 (6)
PND 14 | 8.00 ± 0.00 (6) | 7.71 ± 0.18 (7) | 7.80 ± 0.20 (5) | 7.80 ± 0.20 (5) | 8.00 ± 0.00 (6)
PND 17 | 8.00 ± 0.00 (6) | 7.71 ± 0.18 (7) | 7.80 ± 0.20 (5) | 7.80 ± 0.20 (5) | 8.00 ± 0.00 (6)
PND 21 | 8.00 ± 0.00 (6) | 7.71 ± 0.18 (7) | 7.80 ± 0.20 (5) | 7.80 ± 0.20 (5) | 8.00 ± 0.00 (6)
Survival/Litter
Total Dead: PND 1–4^e,f^ | 16 (3) | 3 (1) | 1 (1) | 5 (3) | 2 (1)
Total Dead: PND 4–21^e,f^ | 0 (0) | 2 (2) | 1 (1) | 1 (1) | 0 (0)
Dead/Litter: PND 1–4^a,b^ | 1.231 ± 0.871 (13) | 0.231 ± 0.231 (13) | 0.200 ± 0.200 (5) | 0.455 ± 0.282 (11) | 0.333 ± 0.333 (6)
Dead/Litter: PND 4–21^a,b^ | 0.000 ± 0.000 (6) | 0.286 ± 0.184 (7) | 0.200 ± 0.200 (5) | 0.200 ± 0.200 (5) | 0.000 ± 0.000 (6)
Survival Ratio: PND 1–4^a,b,g^ | 0.923 ± 0.077 (13) | 0.994 ± 0.006 (13) | 1.000 ± 0.000 (5) | 0.977 ± 0.017 (11) | 0.987 ± 0.013 (6)
Survival Ratio: PND 4–21^a,b,h^ | 1.000 ± 0.000 (6) | 0.964 ± 0.023 (7) | 0.975 ± 0.025 (5) | 0.975 ± 0.025 (5) | 1.000 ± 0.000 (6)

The 40,000 ppm group was euthanized due to moribund condition or found dead on gestation day 11 or 13.

PND = postnatal day.

^a^ Each exposed group was compared to the vehicle control group with the Shirley test when a trend was present (p ≤ 0.01 from the Jonckheere trend test) or with the Dunn test when no trend was present. No statistically significant findings were noted at p ≤ 0.05.

^b^ Data are presented as mean ± standard error (number of litters).

^c^ Litters in which the male/female pup counts were inconsistent between PND 1 and PND 4 were excluded from the male/female-specific endpoints.

^d^ [100 × (number of live males in exposure group)/(number of live males and females in exposure group)](number of pups).

^e^ No statistical analysis performed on this endpoint.

^f^ Total number of dead pups in exposure group (number of litters contributing dead pups).

^g^ Survival/litter: Number of live pups prestandardization on PND 4/total live pups on PND 1.

^h^ Survival/litter: Number of live pups on PND 21/number of live pups poststandardization on PND 4.

Table 8 Summary of Preweaning F_1_ Male and Female Rat Pup Mean Body Weights Following Perinatal Exposure to Tris(chloropropyl) Phosphate

Parameter | 0 ppm | 2,500 ppm | 5,000 ppm | 10,000 ppm | 20,000 ppm
Male (g)
PND 1^a,b,c,d^ | 6.95 ± 0.09 (9) | 7.13 ± 0.15 (10) | 7.31 ± 0.14 (3) | 7.30 ± 0.16 (8) | 6.90 ± 0.14 (5)
PND 4^e,f,g,h^ | 10.62 ± 0.19** (6) | 10.12 ± 0.48 (7) | 10.20 ± 0.24 (5) | 10.61 ± 0.30 (5) | 9.06 ± 0.33* (6)
PND 7^e,f,h^ | 16.10 ± 0.54** (6) | 15.07 ± 0.79 (7) | 14.82 ± 0.48 (5) | 16.34 ± 0.44 (5) | 13.06 ± 0.80* (6)
PND 14^e,f,h^ | 30.94 ± 1.26** (6) | 30.03 ± 1.53 (7) | 29.56 ± 0.91 (5) | 31.15 ± 1.29 (5) | 24.80 ± 1.44* (6)
PND 21^e,f,h^ | 51.91 ± 1.72** (6) | 47.21 ± 2.11 (7) | 45.17 ± 1.13* (5) | 46.31 ± 1.50 (5) | 35.79 ± 1.65** (6)
Female (g)
PND 1^a,b,c,d^ | 6.63 ± 0.13 (9) | 6.73 ± 0.13 (10) | 6.91 ± 0.13 (3) | 6.83 ± 0.08 (8) | 6.61 ± 0.14 (5)
PND 4^e,f,g,h^ | 10.25 ± 0.28** (6) | 9.98 ± 0.45 (7) | 9.82 ± 0.19 (5) | 9.73 ± 0.25 (5) | 8.80 ± 0.24* (6)
PND 7^e,f,h^ | 15.50 ± 0.46** (6) | 13.99 ± 0.76 (7) | 14.05 ± 0.22 (5) | 14.67 ± 0.25 (5) | 12.74 ± 0.68** (6)
PND 14^e,f,h^ | 30.10 ± 1.12** (6) | 28.04 ± 1.47 (7) | 28.66 ± 1.03 (5) | 29.72 ± 1.57 (5) | 24.48 ± 0.99* (6)
PND 21^e,f,h^ | 48.13 ± 1.78** (6) | 43.60 ± 1.73 (7) | 42.85 ± 1.10 (5) | 44.07 ± 1.91 (5) | 34.95 ± 1.24** (6)
Male and Female (g)
PND 1^a,b,c^ | 6.81 ± 0.08 (13) | 6.79 ± 0.20 (13) | 6.90 ± 0.15 (5) | 6.98 ± 0.34 (11) | 6.71 ± 0.11 (6)
PND 4^e,f,g,h^ | 10.43 ± 0.22** (6) | 10.05 ± 0.40 (7) | 10.03 ± 0.19 (5) | 10.17 ± 0.26 (5) | 8.94 ± 0.28** (6)
PND 7^e,f,h^ | 15.80 ± 0.48** (6) | 14.50 ± 0.76 (7) | 14.47 ± 0.34 (5) | 15.50 ± 0.28 (5) | 12.89 ± 0.73** (6)
PND 14^e,f,h^ | 30.52 ± 1.16** (6) | 28.99 ± 1.48 (7) | 29.16 ± 0.96 (5) | 30.43 ± 1.41 (5) | 24.62 ± 1.19* (6)
PND 21^e,f,h^ | 50.02 ± 1.64** (6) | 45.32 ± 1.89 (7) | 44.12 ± 1.12 (5) | 45.19 ± 1.69 (5) | 35.42 ± 1.42** (6)

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

The 40,000 ppm group was euthanized due to moribund condition or found dead on gestation day 11 or 13.

PND = postnatal day.

^a^ Each exposed group was compared to the vehicle control group with the Williams test when a trend was present (p ≤ 0.01 from the Jonckheere trend test) or with the Dunnett test when no trend was present.

^b^ Data are presented as mean ± standard error (number of litters).

^c^ Total pup weight at PND 1 divided by number of live pups at PND 1.

^d^ Litters in which the male/female pup counts were inconsistent between PND 1 and PND 4 were excluded from the male/female-specific endpoints.

^e^ Statistical analysis performed using linear mixed models with random litter effect for both trend and pairwise tests, using the Dunnett-Hsu adjustment for multiple comparisons.

^f^ Data are presented as the mean of the litter means ± standard error (number of litters).

^g^ PND 4 poststandardization.

^h^ Individual pup weights first adjusted for live litter size on PND 4 poststandardization.

### Three-month Study (Postweaning Phase)

Male rats in the 20,000 ppm group did not survive to study termination (Table 9). Seven males in this group were euthanized moribund after displaying thinness, lethargy, paleness, and small size on study days 4 and 5, and one male was found dead on study day 5. Additionally, the mean feed consumption by this group was 14% of the control group (Appendix H). The remaining males in the 20,000 ppm group were removed from the study on study day 5. All females in the 20,000 ppm group and all animals in the remaining groups (males and females) survived until study termination with no clinical signs of toxicity (Table 9, Table 10; Appendix H).

Table 9 Summary of Survival and Mean Body Weights of Male Rats in the Perinatal and Three-month Feed Study of Tris(chloropropyl) Phosphate

Study Day^a^ | 0 ppm | | 2,500 ppm | | | 5,000 ppm | | | 10,000 ppm | | | 20,000 ppm
Study Day^a^ | Av. Wt. (g)^b^ | No. of Litters | Av. Wt. (g) | Wt. (% of Controls) | No. of Litters | Av. Wt. (g) | Wt. (% of Controls) | No. of Litters | Av. Wt. (g) | Wt. (% of Controls) | No. of Litters | Av. Wt. (g) | Wt. (% of Controls) | No. of Litters
1 | 50.6 | 5 | 45.2 | 89.3 | 5 | 44.0 | 87.1 | 5 | 45.9 | 90.8 | 5 | 34.5 | 68.3 | 5
9 | 84.2 | 5 | 77.8 | 92.4 | 5 | 75.2 | 89.4 | 5 | 79.3 | 94.3 | 5 | –^c^ | – | –
16 | 125.6 | 5 | 118.3 | 94.2 | 5 | 112.8 | 89.8 | 5 | 115.7 | 92.1 | 5 | – | – | –
23 | 171.3 | 5 | 163.3 | 95.3 | 5 | 158.5 | 92.6 | 5 | 157.0 | 91.7 | 5 | – | – | –
30 | 213.8 | 5 | 204.7 | 95.7 | 5 | 199.7 | 93.4 | 5 | 202.6 | 94.7 | 5 | – | – | –
37 | 266.4 | 5 | 247.7 | 93.0 | 5 | 239.9 | 90.1 | 5 | 246.8 | 92.6 | 5 | – | – | –
44 | 298.5 | 5 | 277.7 | 93.0 | 5 | 273.0 | 91.5 | 5 | 280.0 | 93.8 | 5 | – | – | –
51 | 324.4 | 5 | 302.8 | 93.3 | 5 | 300.3 | 92.6 | 5 | 307.5 | 94.8 | 5 | – | – | –
58 | 346.5 | 5 | 324.6 | 93.7 | 5 | 320.9 | 92.6 | 5 | 327.4 | 94.5 | 5 | – | – | –
65 | 363.0 | 5 | 339.0 | 93.4 | 5 | 335.2 | 92.3 | 5 | 344.9 | 95.0 | 5 | – | – | –
72 | 377.2 | 5 | 351.8 | 93.3 | 5 | 351.0 | 93.1 | 5 | 360.1 | 95.5 | 5 | – | – | –
79 | 387.3 | 5 | 357.5 | 92.3 | 5 | 360.1 | 93.0 | 5 | 369.2 | 95.3 | 5 | – | – | –
86 | 394.3 | 5 | 365.2 | 92.6 | 5 | 368.9 | 93.6 | 5 | 380.8 | 96.6 | 5 | – | – | –
93 | 404.8 | 5 | 376.1 | 92.9 | 5 | 377.2 | 93.2 | 5 | 390.0 | 96.3 | 5 | – | – | –
EOS | 404.8 | 5 | 379.6 | 93.8 | 5 | 381.6 | 94.3 | 5 | 392.1 | 96.9 | 5 | – | – | –

No trend or pairwise statistical tests were performed on these data.

EOS = end of study.

^a^ Study day 1 is the day animals were placed on study after pups were weaned.

^b^ Average weights shown are mean of litter means.

^c^ All male rats in the 20,000 ppm group were euthanized moribund or found dead by study day 5.

Table 10 Summary of Survival and Mean Body Weights of Female Rats in the Perinatal and Three-month Feed Study of Tris(chloropropyl) Phosphate

Study Day^a^ | 0 ppm | | 2,500 ppm | | | 5,000 ppm | | | 10,000 ppm | | | 20,000 ppm
Study Day^a^ | Av. Wt. (g)^b^ | No. of Litters | Av. Wt. (g) | Wt. (% of Controls) | No. of Litters | Av. Wt. (g) | Wt. (% of Controls) | No. of Litters | Av. Wt. (g) | Wt. (% of Controls) | No. of Litters | Av. Wt. (g) | Wt. (% of Controls) | No. of Litters
1 | 47.5 | 5 | 42.4 | 89.2 | 5 | 42.1 | 88.6 | 5 | 44.0 | 92.6 | 5 | 32.8 | 69.0 | 5
9 | 75.6 | 5 | 73.3 | 97.0 | 5 | 74.1 | 98.1 | 5 | 78.1 | 103.3 | 5 | 57.4 | 75.9 | 5
16 | 106.9 | 5 | 103.4 | 96.7 | 5 | 105.5 | 98.7 | 5 | 109.2 | 102.1 | 5 | 83.9 | 78.5 | 5
23 | 137.5 | 5 | 134.5 | 97.8 | 5 | 138.4 | 100.6 | 5 | 140.8 | 102.4 | 5 | 108.0 | 78.5 | 5
30 | 161.4 | 5 | 155.2 | 96.1 | 5 | 159.4 | 98.7 | 5 | 163.2 | 101.1 | 5 | 133.6 | 82.8 | 5
37 | 181.0 | 5 | 172.6 | 95.4 | 5 | 174.7 | 96.5 | 5 | 184.7 | 102.0 | 5 | 153.0 | 84.5 | 5
44 | 196.4 | 5 | 186.7 | 95.1 | 5 | 190.6 | 97.0 | 5 | 196.4 | 100.0 | 5 | 170.6 | 86.9 | 5
51 | 208.6 | 5 | 196.5 | 94.2 | 5 | 199.3 | 95.5 | 5 | 207.5 | 99.5 | 5 | 179.4 | 86.0 | 5
58 | 216.0 | 5 | 207.8 | 96.2 | 5 | 210.7 | 97.5 | 5 | 216.0 | 100.0 | 5 | 189.5 | 87.7 | 5
65 | 223.0 | 5 | 209.8 | 94.1 | 5 | 215.9 | 96.8 | 5 | 221.0 | 99.1 | 5 | 195.4 | 87.6 | 5
72 | 232.3 | 5 | 221.9 | 95.5 | 5 | 224.5 | 96.6 | 5 | 232.6 | 100.1 | 5 | 206.1 | 88.7 | 5
79 | 236.5 | 5 | 222.6 | 94.1 | 5 | 230.3 | 97.4 | 5 | 232.5 | 98.3 | 5 | 208.2 | 88.0 | 5
86 | 238.6 | 5 | 230.3 | 96.5 | 5 | 232.1 | 97.3 | 5 | 237.9 | 99.7 | 5 | 209.1 | 87.7 | 5
93 | 242.8 | 5 | 232.4 | 95.7 | 5 | 240.5 | 99.1 | 5 | 244.9 | 100.9 | 5 | 216.5 | 89.2 | 5
EOS | 242.2 | 5 | 232.5 | 96.0 | 5 | 235.0 | 97.0 | 5 | 242.9 | 100.3 | 5 | 211.9 | 87.5 | 5

No trend or pairwise statistical tests were performed on these data.

EOS = end of study.

^a^ Study day 1 is the day animals were placed on study after pups were weaned.

^b^ Average weights shown are mean of litter means.

Mean body weights of the remaining male rats exposed to TCPP were within 10% of the control group by study termination (Table 9). The mean body weight of the 20,000 ppm females was 31% lower than that of the control group on study day 1, but only 12% lower than that of the control group by study termination (Table 10). Group mean body weights of the 2,500, 5,000, and 10,000 ppm male and female rats were approximately 7%–13% lower than those of the respective control groups at the beginning of the postweaning period (Table 9, Table 10; Figure 1); however, weight gain was sufficient enough such that mean body weights of male and female rats in these groups were within 6% of those of the respective control groups by study termination (Table 9, Table 10; Appendix H).

Figure 1

Growth Curves for Male and Female Rats in the Perinatal and Three-month Feed Study of Tris(chloropropyl) Phosphate

Growth curves are shown for (A) males and (B) females. Males in the 20,000 ppm group (black circle) were removed from study on day 5.

In general, feed consumption by male and female rats in TCPP-exposed groups was lower (males = 13%–86%; females = 5%–47%) than that of the control groups during the first week of the study (Table 11, Table 12; Appendix H). Feed consumption values fluctuated over the course of the study but were within approximately 10% of the control groups at study termination with the exception of female rats in the 20,000 ppm group, whose consumption was 18% lower than that of the female control group at study termination. For males, average daily TCPP intakes based on weekly average feed ingestion and body weight were estimated to be 223, 431, and 911 mg/kg/day for males in the 2,500, 5,000, and 10,000 ppm groups, respectively; for females, they were estimated to be 236, 458, 906, and 1,890 mg/kg/day in the 2,500, 5,000, 10,000, and 20,000 ppm groups, respectively (Appendix H). Table 11 and Table 12 highlight feed consumption (i.e., feed [g/day]) and estimated TCPP intake (i.e., dose [mg/kg/day]) at select time points. Overall, the increase in TCPP intake across groups was of similar proportion to the increase in exposure concentration for both sexes.

Table 11 Summary of Feed and Tris(chloropropyl) Phosphate Consumption of Male Rats in the Perinatal and Three-month Feed Study

Week | 0 ppm | 2,500 ppm | | 5,000 ppm | | 10,000 ppm | | 20,000 ppm
Week | Feed (g/day)^a^ | Feed (g/day) | Dose (mg/kg/day)^b^ | Feed (g/day) | Dose (mg/kg/day) | Feed (g/day) | Dose (mg/kg/day) | Feed (g/day) | Dose (mg/kg/day)
1 | 8.3 | 7.2 | 398.6 | 6.4 | 726.8 | 6.9 | 1,502.9 | 1.2 | 695.0
4 | 21.0 | 19.9 | 304.7 | 18.6 | 586.7 | 20.8 | 1,325.0 | –^c^ | –
13 | 20.8 | 20.1 | 137.6 | 18.1 | 245.4 | 19.8 | 520.0 | – | –

No trend or pairwise statistical tests were performed on these data.

^a^ Grams of feed consumed/animal/day.

^b^ Milligrams of tris(chloropropyl) phosphate consumed/kilogram body weight/day.

^c^ All male rats in the 20,000 ppm group were euthanized moribund or found dead by study day 5.

Table 12 Summary of Feed and Tris(chloropropyl) Phosphate Consumption of Female Rats in the Perinatal and Three-month Feed Study

Week | 0 ppm | 2,500 ppm | | 5,000 ppm | | 10,000 ppm | | 20,000 ppm
Week | Feed (g/day)^a^ | Feed (g/day) | Dose (mg/kg/day)^b^ | Feed (g/day) | Dose (mg/kg/day) | Feed (g/day) | Dose (mg/kg/day) | Feed (g/day) | Dose (mg/kg/day)
1 | 8.6 | 8.1 | 478.0 | 7.7 | 914.9 | 8.2 | 1,864.9 | 4.6 | 2,808.3
4 | 15.3 | 15.0 | 278.8 | 14.9 | 538.5 | 15.6 | 1,108.0 | 13.3 | 2,462.7
13 | 15.9 | 14.0 | 152.0 | 13.7 | 295.1 | 13.9 | 584.4 | 13.0 | 1,243.4

No trend or pairwise statistical tests were performed on these data.

^a^ Grams of feed consumed/animal/day.

^b^ Milligrams of tris(chloropropyl) phosphate consumed/kilogram body weight/day.

At study termination, significant exposure concentration-related decreases in alanine aminotransferase (ALT) and alkaline phosphatase (ALP) activities were observed in both male and female rats (Table 13). Cholesterol concentrations were significantly increased in the 10,000 ppm male and the 10,000 and 20,000 ppm female rats (Table 13). All other statistically significant clinical pathology changes were minimal or inconsistent and not considered due to TCPP exposure (Appendix H).

Table 13 Summary of Select Clinical Chemistry Data for Male and Female Rats in the Perinatal and Three-month Feed Study of Tris(chloropropyl) Phosphate^a,b^

| 0 ppm | 2,500 ppm | 5,000 ppm | 10,000 ppm | 20,000 ppm
Male
n | 5 | 5 | 5 | 5 | –^c^
Alanine Aminotransferase (IU/L) | 51.9 ± 1.8** | 40.7 ± 1.4** | 40.4 ± 1.1** | 31.0 ± 1.2** | –
Alkaline Phosphatase (IU/L) | 196.8 ± 6.7** | 178.8 ± 14.4 | 160.1 ± 4.2* | 143.8 ± 3.5** | –
Cholesterol (mg/dL) | 127.5 ± 4.0* | 141.8 ± 7.6 | 139.7 ± 6.4 | 149.2 ± 5.0* | –
Female
n | 5 | 5 | 5 | 5 | 5
Alanine Aminotransferase (IU/L) | 48.9 ± 1.9** | 46.1 ± 2.1 | 39.2 ± 2.5* | 22.6 ± 1.0** | 16.3 ± 1.4**
Alkaline Phosphatase (IU/L) | 162.8 ± 12.9** | 143.0 ± 7.4 | 134.4 ± 10.2 | 109.2 ± 6.7* | 109.9 ± 8.2*
Cholesterol (mg/dL) | 127.1 ± 2.9** | 134.6 ± 7.8 | 136.4 ± 4.0 | 153.7 ± 3.7* | 163.3 ± 8.9*

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ Data are presented as mean of the litter means ± standard error. “n” is the number of litters.

^b^ Statistical analysis performed using a bootstrapped Jonckheere test for trend and a Datta-Satten modified Wilcoxon test with Hommel adjustment for pairwise comparisons.

^c^ All male rats in the 20,000 ppm group were euthanized moribund or found dead by study day 5.

Exposure-related organ weight changes were observed in the liver and thymus (Table 14). Male rats exposed to 10,000 ppm TCPP had significant increases in absolute (15%) and relative liver weights compared to the control group. Liver weights were within 10% of the control group in male rats exposed to ≤5,000 ppm TCPP. A similar pattern was observed in female rats with absolute liver weights 13% and 19% higher in female rats exposed to 10,000 and 20,000 ppm TCPP, respectively. Relative liver weights in female rats were also increased in a significant exposure concentration-related manner (Table 14).

Table 14 Summary of Select Organ Weights and Organ-Weight-to-Body-Weight Ratios for Male and Female Rats in the Perinatal and Three-month Feed Study of Tris(chloropropyl) Phosphate^a,b^

| 0 ppm | 2,500 ppm | 5,000 ppm | 10,000 ppm | 20,000 ppm
Male
n | 5 | 5 | 5 | 5 | –^c^
Terminal Body Wt. (g) | 404.8 ± 5.9 | 379.6 ± 6.4* | 381.6 ± 8.1 | 392.1 ± 6.5 | –
Liver
Absolute (g) | 15.82 ± 0.17** | 14.92 ± 0.38 | 15.88 ± 0.49 | 18.18 ± 0.55** | –
Relative (mg/g)^d^ | 39.10 ± 0.58** | 39.28 ± 0.73 | 41.65 ± 1.06 | 46.32 ± 1.09** | –
Thymus
Absolute (g) | 0.336 ± 0.015** | 0.407 ± 0.030 | 0.427 ± 0.017* | 0.454 ± 0.031** | –
Relative (mg/g) | 0.83 ± 0.04** | 1.07 ± 0.08* | 1.12 ± 0.04** | 1.15 ± 0.07** | –
Female
n | 5 | 5 | 5 | 5 | 5
Terminal Body Wt. (g) | 242.2 ± 3.1** | 232.5 ± 7.4 | 235.0 ± 4.5 | 242.9 ± 3.7 | 211.9 ± 4.4**
Liver
Absolute (g) | 8.65 ± 0.42** | 8.89 ± 0.29 | 9.23 ± 0.26 | 9.78 ± 0.32 | 10.33 ± 0.25**
Relative (mg/g) | 35.64 ± 1.52** | 38.17 ± 0.25 | 39.25 ± 0.87* | 40.25 ± 0.84** | 48.76 ± 0.54**
Thymus
Absolute (g) | 0.244 ± 0.009 | 0.279 ± 0.024 | 0.321 ± 0.026 | 0.335 ± 0.028* | 0.298 ± 0.016
Relative (mg/g) | 1.01 ± 0.04** | 1.20 ± 0.08 | 1.36 ± 0.08* | 1.38 ± 0.10* | 1.41 ± 0.07**

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ Data are presented as mean of the litter means ± standard error. “n” is the number of litters.

^b^ Statistical analysis performed by the Jonckheere (trend) and the Williams or Dunnett (pairwise) tests.

^c^ All male rats in the 20,000 ppm group were euthanized moribund or found dead by study day 5.

^d^ Relative organ weights (organ-weight-to-body-weight ratios) are given as mg organ weight/g body weight.

Absolute and relative thymus weights of male and female rats were higher in TCPP-exposed groups (Table 14). Absolute thymus weights were 21%–35% higher in all TCPP-exposed male rats with statistical significance achieved in the 5,000 and 10,000 ppm groups. Similarly, relative thymus weights were significantly increased in all TCPP-exposed male rats when compared to those of the control group. TCPP-exposed female rats exhibited a 14%–37% increase in absolute thymus weights; the differences were statistically significant in the 10,000 ppm group. At the highest exposure concentration of 20,000 ppm, absolute female thymus weights were 22% higher than those of the control group but not statistically significant. Relative thymus weights were higher in all TCPP-exposed female groups with statistical significance in groups exposed to ≥5,000 ppm.

Alterations in kidney, lung, and heart weights were observed in both male and female rats exposed to TCPP (Appendix H). These changes were not considered to be related to exposure and did not have a histological correlate upon tissue examination.

There were no changes in weights of the testis or epididymis, or alterations in sperm parameters attributable to TCPP exposure (Appendix H). Observed changes—although at times statistically significant—were of small magnitude, were not related to exposure concentration, did not exhibit histopathological correlates, and were consistent with normal biological variability.

#### Histopathology

This section describes the statistically significant or biologically noteworthy changes in the incidence of nonneoplastic lesions of the liver and thymus.

Liver: In male and female rats, there was minimal bile duct hyperplasia in the 10,000 and 20,000 ppm (female only) groups (Table 15). This lesion is characterized by increased numbers (2–5) of biliary ductules of variable sizes, lined by well-differentiated low cuboidal epithelial cells in the portal areas. The occasional presence of inflammatory cells, predominantly lymphocytes, and macrophages and/or fibroblasts surrounded by scant collagen, expanded the portal areas. There were no apparent histological correlates to the increases in absolute and relative liver weights in male or female rats.

Table 15 Incidences of Nonneoplastic Lesions of the Liver in Male and Female Rats in the Perinatal and Three-month Feed Study of Tris(chloropropyl) Phosphate

| 0 ppm | 2,500 ppm | 5,000 ppm | 10,000 ppm | 20,000 ppm
Male
Liver^a^ | 10 | 10 | 10 | 10 | –^b^
Bile duct, hyperplasia^c^ | 0 | 0 | 0 | 8** (1.0)^d^ | –
Female
Liver | 10 | 10 | 10 | 10 | 10
Bile duct, hyperplasia | 0** | 0 | 0 | 4* (1.0) | 5* (1.0)

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control indicates a significant trend test.

* Statistically significant at p ≤ 0.05 by the Cochran-Armitage (trend) test or Fisher’s exact (pairwise) test; **p ≤ 0.01.

^a^ Number of animals examined microscopically.

^b^ All male rats in the 20,000 ppm group were euthanized moribund or found dead by study day 5 and were excluded from analysis.

^c^ Number of animals with lesion.

^d^ Average severity grade of observed lesion in affected animals: 1 = minimal; 2 = mild; 3 = moderate; 4 = marked.

Thymus: In male and female rats, there were significantly increased relative thymus weights in all exposed groups with the exception of the female 2,500 ppm group (Table 14). Given that this was an unusual finding within a subchronic rodent study, additional morphometry analysis was conducted with hematoxylin and eosin (H&E)-stained sections to characterize the histological changes. The increases in thymus weights manifested microscopically in male rats with significantly increased total area of the thymus and expanded thymic cortices in all exposed groups compared to those of the control groups as demonstrated by morphometry. In female rats, only the 10,000 ppm group showed significantly increased thymic area with expanded cortices and medullae (Table 16; Appendix H). These histological changes correlated with thymus weights (Table 14).

Table 16 Image Analysis of Thymus Size for Male and Female Rats in the Perinatal and Three-month Feed Study of Tris(chloropropyl) Phosphate^a,b^

| 0 ppm | 2,500 ppm | 5,000 ppm | 10,000 ppm | 20,000 ppm
Male
Thymus area (mm^2^) | 29.0 ± 1.6 | 37.9 ± 2.5** | 38.3 ± 2.2** | 39.8 ± 2.0** | –^c^
Cortex area (mm^2^) | 20.3 ± 1.3 | 27.0 ± 1.8** | 28.3 ± 1.6** | 29.7 ± 1.4** | –
Medulla area (mm^2^) | 8.7 ± 0.8 | 10.9 ± 0.9 | 10.0 ± 0.9 | 10.0 ± 0.8 | –
Female
Thymus area (mm^2^) | 22.7 ± 1.4 | 24.7 ± 2.6 | 29.4 ± 2.7 | 33.1 ± 2.4** | 25.6 ± 3.0
Cortex area (mm^2^) | 17.7 ± 1.0 | 17.4 ± 1.6 | 21.6 ± 2.1 | 24.8 ± 1.6* | 18.5 ± 2.2
Medulla area (mm^2^) | 5.0 ± 0.5 | 7.3 ± 1.1 | 7.9 ± 0.8 | 8.2 ± 1.1* | 7.1 ± 1.1

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ Data are presented as mean ± standard error quantitated with Definiens Tissue Studio^®^ software.

^b^ Statistical analysis performed by a one-sided Dunnett’s test.

^c^ All male rats in the 20,000 ppm group were euthanized moribund or found dead by study day 5.

### Exposure Concentration Selection Rationale for Two-year Study in Rats

During gestation, maternal toxicity was observed in dams exposed to 40,000 ppm TCPP, which resulted in removal of that group from study. In the lactation period, dams and offspring exposed to ≤20,000 ppm TCPP did not show significant signs of toxicity. Postweaning (PND 21), male rats exposed to 20,000 ppm TCPP were removed on study day 5 because of the presence of adverse clinical signs and reductions in mean body weight and feed consumption. Males exposed to ≤10,000 ppm TCPP and all female rats exposed to TCPP survived to study termination with no clinical signs of toxicity or nonneoplastic lesions of concern for chronic exposure. In parallel with this study, findings from additional NTP research suggested that PND 21 was potentially too early for weaning of Sprague Dawley rats and a global decision to extend the weaning period to PND 28 was made to reduce stress on offspring and increase survival. Concentrations for the 2-year study were selected to be 0, 2,500, 5,000, 10,000, or 20,000 ppm TCPP in feed. The extended weaning period and results from the 3-month study were the primary rationale for a top exposure concentration of 20,000 ppm TCPP.

### Two-year Study (Perinatal Phase)

No exposure-related effects were observed on the pregnancy status, maternal survival, or number of dams that littered (Table 17).

Table 17 Summary of the Disposition of F_0_ Female Rats during Perinatal Exposure in the Perinatal and Two-year Feed Study of Tris(chloropropyl) Phosphate

| 0 ppm | 2,500 ppm | 5,000 ppm | 10,000 ppm | 20,000 ppm
Reproductive Performance
Time-mated Females (GD 6) | 38 | 38 | 38 | 38 | 38
Females Pregnant (%)^a^ | 35 (92.1) | 35 (92.1) | 36 (94.7) | 35 (92.1) | 36 (94.7)
Females Not Pregnant (%)^b^ | 3 (7.9) | 3 (7.9) | 2 (5.3) | 3 (7.9) | 2 (5.3)
Dams Not Delivering with Evidence of Pregnancy (%) | 3 (8.6) | 0 | 0 | 1 (2.8) | 1 (2.8)
Dams with Litters on LD 0 (%)^a,b,c^ | 31 (88.6) | 35 (100) | 36 (100) | 34 (97.1) | 34 (94.4)
Litters Poststandardization (PND 4)^d^ | 30 | 30 | 30 | 27 | 30
Weaned Males/Females | 122/117 | 120/120 | 120/120 | 110/105 | 118/117

GD = gestation day; LD = lactation day; PND = postnatal day.

^a^ Statistical analysis performed by the Cochran-Armitage (trend) and Fisher’s exact (pairwise) tests. No statistically significant findings were noted at p ≤ 0.05.

^b^ Percentage is given as a portion of pregnant dams.

^c^ Animals removed from study between mating and littering were excluded from percentage values (one dam in the 0 ppm group and one dam in the 20,000 ppm group).

^d^ Standardization to eight pups/litter (four pups/sex).

There were exposure-related effects on maternal body weights during gestation with a significant decrease of up to 9% in the 20,000 ppm group at GD 9 compared to the control group, but the magnitude of the effect subsided as gestation progressed (Table 18). During lactation, a significant decrease was observed in mean body weights of up to 12% in the 20,000 ppm group compared to that of the control group, with the magnitude of the effect decreasing after the LD 14 time point (likely coinciding with the reduced feed consumption that resulted from F_1_ pups switching from nursing to consuming feed).

Table 18 Summary of Mean Body Weights and Body Weight Gains of F_0_ Female Rats during Gestation and Lactation in the Perinatal and Two-year Feed Study of Tris(chloropropyl) Phosphate

Parameter^a,b^ | 0 ppm | 2,500 ppm | 5,000 ppm | 10,000 ppm | 20,000 ppm
Gestation Body Weight
Gestation Day
6 | 235.3 ± 2.2 (34) | 234.0 ± 2.2 (35) | 233.6 ± 2.3 (36) | 233.4 ± 2.1 (35) | 231.9 ± 2.1 (36)
9 | 251.3 ± 2.2** (34) | 251.4 ± 1.9 (35) | 248.8 ± 2.0 (36) | 245.5 ± 2.6 (35) | 228.9 ± 3.2** (36)
12 | 264.9 ± 2.4** (34) | 265.4 ± 2.0 (35) | 263.5 ± 2.1 (36) | 262.4 ± 2.6 (35) | 244.3 ± 4.6** (36)
15 | 286.6 ± 3.1** (34) | 288.7 ± 2.3 (35) | 285.6 ± 2.1 (36) | 284.4 ± 2.4 (35) | 271.5 ± 4.0** (35)^c^
18 | 319.8 ± 4.7 (34) | 325.8 ± 2.9 (35) | 324.4 ± 2.7 (36) | 325.3 ± 3.5 (35) | 312.9 ± 4.5 (35)
21 | 365.0 ± 7.1* (34) | 373.9 ± 3.5 (35) | 371.4 ± 3.4 (36) | 367.5 ± 4.8 (35) | 355.7 ± 5.8 (35)
Gestation Weight Change
Gestation Day Interval
6–9 | 16.0 ± 0.5** (34) | 17.4 ± 0.9 (35) | 15.2 ± 0.8 (36) | 12.1 ± 1.5 (35) | −3.0 ± 3.3** (36)
9–12 | 13.6 ± 0.6** (34) | 14.0 ± 0.6 (35) | 14.7 ± 0.7 (36) | 16.9 ± 1.1 (35) | 15.4 ± 2.5 (36)
12–15 | 21.7 ± 1.2 (34) | 23.3 ± 0.8 (35) | 22.0 ± 0.8 (36) | 22.0 ± 1.3 (35) | 24.7 ± 1.2 (35)^c^
15–18 | 33.2 ± 1.9** (34) | 37.1 ± 1.1 (35) | 38.8 ± 1.1** (36) | 40.9 ± 1.6** (35) | 41.4 ± 1.6** (35)
18–21 | 45.2 ± 2.6** (34) | 48.1 ± 1.1 (35) | 47.0 ± 1.2 (36) | 42.2 ± 2.2 (35) | 42.8 ± 1.7 (35)
6–21 | 129.6 ± 5.7 (34) | 139.8 ± 3.0 (35) | 137.7 ± 3.0 (36) | 134.1 ± 4.4 (35) | 124.0 ± 5.4 (35)
Lactation Body Weight
Lactation Day
1 | 276.3 ± 2.6 (31) | 278.8 ± 2.2 (35) | 277.9 ± 2.5 (35) | 281.3 ± 2.4 (34) | 268.1 ± 2.8 (34)
4 | 290.0 ± 2.9** (31) | 293.7 ± 2.2 (35) | 293.9 ± 2.3 (35) | 289.1 ± 2.8 (34) | 271.7 ± 2.9** (34)
7 | 299.6 ± 3.0** (30) | 301.6 ± 2.1 (30) | 302.0 ± 2.7 (29) | 297.2 ± 3.4 (27) | 275.8 ± 3.3** (30)
10 | 309.8 ± 3.3** (30) | 308.4 ± 2.6 (30) | 307.8 ± 2.7 (29) | 301.9 ± 3.3 (27) | 279.5 ± 3.0** (30)
14 | 317.6 ± 3.2** (30) | 314.5 ± 2.8 (30) | 315.7 ± 3.1 (29) | 309.1 ± 3.3 (27) | 280.3 ± 3.4** (30)
17 | 308.5 ± 3.1** (30) | 308.9 ± 2.3 (30) | 310.4 ± 2.7 (29) | 305.6 ± 3.0 (27) | 278.3 ± 3.5** (30)
21 | 299.2 ± 3.0** (30) | 301.7 ± 2.2 (30) | 300.9 ± 2.2 (29) | 302.5 ± 2.7 (27) | 272.3 ± 3.1** (30)
24 | 286.5 ± 3.1* (30) | 288.9 ± 2.7 (30) | 294.0 ± 2.5 (29) | 295.5 ± 2.9 (27) | 271.1 ± 3.4** (30)
28 | 279.9 ± 3.2 (30) | 281.1 ± 2.8 (30) | 283.7 ± 3.2 (29) | 285.4 ± 2.6 (27) | 271.2 ± 3.0 (30)
Lactation Weight Change
Lactation Day Interval
1–4 | 13.7 ± 1.3** (31) | 14.9 ± 1.1 (35) | 16.0 ± 1.4 (35) | 7.8 ± 1.9** (34) | 3.5 ± 1.5** (34)
4–7 | 9.1 ± 1.8 (30) | 7.7 ± 1.6 (30) | 8.2 ± 1.4 (29) | 6.9 ± 2.0 (27) | 3.3 ± 2.3 (30)
7–10 | 10.2 ± 1.4** (30) | 6.8 ± 1.4 (30) | 5.8 ± 1.4 (29) | 4.7 ± 2.1* (27) | 3.7 ± 1.8** (30)
10–14 | 7.8 ± 1.9* (30) | 6.1 ± 1.9 (30) | 7.9 ± 1.8 (29) | 7.1 ± 1.8 (27) | 0.9 ± 1.7* (30)
14–17 | −9.1 ± 1.8* (30) | −5.6 ± 1.4 (30) | −5.4 ± 2.0 (29) | −3.4 ± 2.2 (27) | −2.0 ± 1.6* (30)
17–21 | −9.3 ± 1.2* (30) | −7.1 ± 1.4 (30) | −9.5 ± 1.6 (29) | −3.2 ± 2.1* (27) | −6.0 ± 1.9 (30)
21–24 | −12.7 ± 1.9** (30) | −12.9 ± 1.5 (30) | −6.9 ± 1.6* (29) | −7.0 ± 1.5* (27) | −1.2 ± 1.7** (30)
24–28 | −6.6 ± 1.3 (30) | −7.8 ± 1.5 (30) | −10.3 ± 2.2 (29) | −10.1 ± 1.8 (27) | 0.2 ± 1.7* (30)
1–28 | 3.0 ± 2.1 (30) | 2.1 ± 2.2 (30) | 5.5 ± 2.6 (29) | 3.0 ± 2.5 (27) | 2.8 ± 2.7 (30)

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ Data are presented as mean ± standard error (number of dams). Body weight data are presented in grams.

^b^ Each exposed group was compared to the vehicle control group with the Williams test when a trend was present (p ≤ 0.01 from the Jonckheere trend test) or with the Dunnett test when no trend was present.

^c^ One animal in the 20,000 ppm group was euthanized due to moribund condition on gestation day 12.

Feed consumption (g/animal/day) by TCPP-exposed dams during gestation and lactation was largely within 10% of control animals (Table 19); slight but significant increases or decreases in feed consumption were observed sporadically during this exposure period. Feed spillage was evident across all exposure groups at multiple times during both gestation and lactation. When spillage occurred, data were not included for a specific dam and time point, which is reflected by the number of dams in Table 19. Chemical intake during gestation (GD 6–21) was estimated to be 183, 368, 749, and 1,544 mg/kg/day for the 2,500, 5,000, 10,000, and 20,000 ppm groups, respectively. Chemical intake during the LD 1–14 interval was estimated to be 389, 763, 1,606, and 3,839 mg/kg/day for the 2,500, 5,000, 10,000, and 20,000 ppm groups, respectively (Table 19). Chemical intake from LD 14 through LD 28 was not calculated because the entire litter ate the feed, and an accurate assessment could not be made. The consumed dose at successive exposure concentrations was of similar proportion to the increase in exposure concentration for both sexes.

Table 19 Summary of Feed and Tris(chloropropyl) Phosphate Consumption by F_0_ Female Rats during Gestation and Lactation in the Perinatal and Two-year Feed Study

Parameter^a^ | 0 ppm | 2,500 ppm | 5,000 ppm | 10,000 ppm | 20,000 ppm
Gestation Day Interval^b,c,d^
6–9 | 18.9 ± 0.3** (34)^e^ | 18.6 ± 0.2 (35) | 18.1 ± 0.4* (27) | 17.0 ± 1.0* (18) | –^f^
9–12 | 19.2 ± 0.4 (34) | 19.2 ± 0.2 (35) | 19.2 ± 0.3 (36) | 19.6 ± 0.3 (32) | 17.4 ± 1.6 (18)
12–15 | 20.2 ± 0.3** (32) | 20.2 ± 0.3 (35) | 20.4 ± 0.3 (35) | 21.4 ± 0.3* (30) | 23.0 ± 0.5** (12)^e^
18–21 | 22.8 ± 0.5 (31) | 23.8 ± 0.3 (35) | 23.8 ± 0.2 (32) | 23.9 ± 0.5 (25) | 24.9 ± 0.2 (7)
6–21 | 20.1 ± 0.3* (34) | 20.4 ± 0.2 (35) | 20.5 ± 0.2 (36) | 20.8 ± 0.3 (34) | 20.4 ± 1.1 (22)
Lactation Day Interval^b,c,d^
1–4 | 35.4 ± 0.6 (19) | 35.6 ± 0.8 (24) | 35.7 ± 0.8 (26) | 32.4 ± 2.1 (8) | –
4–7 | 42.2 ± 0.8* (29) | 42.1 ± 0.6 (30) | 43.0 ± 0.5 (30) | 43.6 ± 1.1 (27) | 44.7 ± 1.9 (29)
7–10 | 50.2 ± 0.7 (30) | 49.4 ± 0.7 (30) | 49.4 ± 0.5 (29) | 48.4 ± 0.9 (25) | 49.4 ± 2.2 (15)
10–14 | 58.6 ± 0.6 (30) | 56.9 ± 0.8 (30) | 57.9 ± 0.6 (30) | 58.8 ± 1.0 (27) | 62.5 ± 2.0 (20)
14–17 | 61.0 ± 0.8** (30) | 61.7 ± 0.7 (30) | 62.0 ± 0.8 (30) | 62.7 ± 1.1 (27) | 70.7 ± 2.4** (26)
17–21 | 72.2 ± 1.0 (30) | 67.1 ± 0.9** (30) | 66.1 ± 0.9** (30) | 68.8 ± 1.1 (26) | 76.8 ± 1.8 (23)
21–24 | 88.8 ± 1.0 (30) | 89.4 ± 1.0 (30) | 88.6 ± 1.3 (30) | 87.5 ± 1.1 (26) | 92.1 ± 2.0 (15)
24–28 | 98.8 ± 1.0** (30) | 101.2 ± 1.1 (30) | 102.2 ± 1.1 (30) | 102.9 ± 1.1 (27) | 101.0 ± 3.4 (13)
1–14 | 48.9 ± 0.7* (30) | 46.9 ± 0.8 (34) | 46.3 ± 1.2 (35) | 47.8 ± 1.6 (32) | 52.9 ± 1.6 (30)
Chemical Intake (mg/kg/day)^g,h^
GD 6–21 | 0.0 ± 0.0 (34) | 182.5 ± 1.6 (35) | 367.7 ± 3.8 (36) | 748.7 ± 8.5 (34) | 1,544 ± 71.6 (22)
LD 1–14 | 0.0 ± 0.0 (30) | 388.9 ± 5.2 (34) | 763.4 ± 17.2 (34) | 1,606 ± 49.9 (32) | 3,839 ± 121.6 (30)

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

GD = gestation day; LD = lactation day.

^a^ Data are presented as mean ± standard error (number of dams).

^b^ Feed consumption data are presented as grams/animal/day.

^c^ Each exposed group was compared to the vehicle control group with the Shirley test when a trend was present (p ≤ 0.01 from the Jonckheere trend test) or with the Dunn test when no trend was present.

^d^ Excludes feed consumption data from cages in which excess feed spillage was observed.

^e^ One dam in the control group and one dam in the 20,000 ppm group were euthanized due to moribund condition on GD 6 and GD 12, respectively. These animals were not included in the analysis.

^f^ No feed consumption data are available for the GD 6–9 and LD 1–4 intervals due to excess feed spillage for every animal in the 20,000 ppm group.

^g^ Chemical intake calculated as ([exposure concentration × feed consumption]/[average body weight of day range]).

^h^ No statistical analysis performed on the chemical intake data.

Total and live litter sizes and survival of the F_1_ rats during lactation were not affected by TCPP exposure (Table 20). An exposure concentration-related decrease in male and female pup mean body weights was observed during lactation; this effect increased over time and plateaued between PND 21 and 28 (Table 21). In the highest exposure group of 20,000 ppm, mean body weights were significantly decreased by 12%–31% in male and 11%–30% in female rats from PND 7 through PND 28 (Table 21). These changes were attributed to lower body weight gains rather than to body weight loss during postnatal exposure.

Table 20 Summary of Mean Litter Size and Survival Ratio of F_1_ Male and Female Rats during Lactation in the Perinatal and Two-year Feed Study of Tris(chloropropyl) Phosphate

Parameter | 0 ppm | 2,500 ppm | 5,000 ppm | 10,000 ppm^a^ | 20,000 ppm
PND 1
Total^b,c,d,e^ | 13.30 ± 0.35 (30) | 12.58 ± 0.38 (33) | 12.46 ± 0.45 (35) | 11.59 ± 0.60 (32) | 12.65 ± 0.51 (34)
Live^b,c,d,e^ | 12.93 ± 0.40 (30) | 12.39 ± 0.41 (33) | 12.29 ± 0.45 (35) | 11.41 ± 0.61 (32) | 12.44 ± 0.59 (34)
% Male/Litter^b,c,d,e^ | 51.0 ± 2.8 (27) | 49.9 ± 2.0 (32) | 50.3 ± 2.6 (34) | 58.6 ± 3.1 (29) | 48.7 ± 2.9 (34)
% Male^e,f,g^ | 51.9 (347) | 50.0 (396) | 48.6 (422) | 58.2 (335) | 50.4 (423)
Male^b,c^
PND 1^d,e^ | 6.67 ± 0.48 (27) | 6.19 ± 0.34 (32) | 6.03 ± 0.28 (34) | 6.72 ± 0.45 (29) | 6.26 ± 0.42 (34)
PND 4 Prestandardization^d,e^ | 6.67 ± 0.48 (27) | 6.19 ± 0.34 (32) | 5.97 ± 0.28 (34) | 6.62 ± 0.45 (29) | 6.36 ± 0.39 (33)
PND 4 Poststandardization | 4.07 ± 0.07 (30) | 4.00 ± 0.00 (30) | 4.00 ± 0.00 (30) | 4.11 ± 0.08 (27) | 4.00 ± 0.07 (30)
Female^b,c^
PND 1^d,e^ | 6.19 ± 0.36 (27) | 6.19 ± 0.32 (32) | 6.38 ± 0.43 (34) | 4.83 ± 0.36 (29) | 6.18 ± 0.42 (34)
PND 4 Prestandardization^d,e^ | 6.15 ± 0.35 (27) | 6.16 ± 0.31 (32) | 6.35 ± 0.43 (34) | 4.76 ± 0.37 (29) | 6.24 ± 0.40 (33)
PND 4 Poststandardization | 3.93 ± 0.07 (30) | 4.00 ± 0.00 (30) | 4.00 ± 0.00 (30) | 3.89 ± 0.08 (27) | 4.00 ± 0.07 (30)
Male and Female^b,c^
PND 4 Prestandardization^e^ | 12.90 ± 0.40 (30) | 12.36 ± 0.40 (33) | 12.20 ± 0.44 (35) | 11.22 ± 0.60 (32) | 12.61 ± 0.47 (33)
PND 4 Poststandardization | 8.00 ± 0.00 (30) | 8.00 ± 0.00 (30) | 8.00 ± 0.00 (30) | 8.00 ± 0.00 (27) | 8.00 ± 0.00 (30)
PND 7 | 8.00 ± 0.00* (30) | 8.00 ± 0.00 (30) | 8.00 ± 0.00 (30) | 7.96 ± 0.04 (27) | 7.93 ± 0.05 (30)
PND 14 | 7.97 ± 0.03 (30) | 8.00 ± 0.00 (30) | 8.00 ± 0.00 (30) | 7.96 ± 0.04 (27) | 7.83 ± 0.10 (30)
PND 21 | 7.97 ± 0.03 (30) | 8.00 ± 0.00 (30) | 8.00 ± 0.00 (30) | 7.96 ± 0.04 (27) | 7.83 ± 0.10 (30)
PND 28 | 7.97 ± 0.03 (30) | 8.00 ± 0.00 (30) | 8.00 ± 0.00 (30) | 7.96 ± 0.04 (27) | 7.83 ± 0.10 (30)
Survival/Litter
Total Dead: PND 1–4^g,h^ | 12 (9) | 7 (6) | 9 (7) | 12 (10) | 14 (7)
Total Dead: PND 4–28^g,h^ | 1 (1) | 0 (0) | 0 (0) | 1 (1) | 5 (3)
Dead/Litter: PND 1–4^b,c^ | 0.40 ± 0.13 (30) | 0.21 ± 0.08 (33) | 0.26 ± 0.10 (35) | 0.38 ± 0.12 (32) | 0.41 ± 0.18 (34)
Dead/Litter: PND 4–21^b,c^ | 0.03 ± 0.03 (30) | 0.00 ± 0.00 (30) | 0.00 ± 0.00 (30) | 0.04 ± 0.04 (27) | 0.17 ± 0.10 (30)
Survival Ratio: PND 1–4^b,c,i^ | 0.997 ± 0.003* (30) | 0.998 ± 0.002 (33) | 0.994 ± 0.003 (35) | 0.985 ± 0.006 (32) | 0.959 ± 0.030 (34)
Survival Ratio: PND 4–28^b,c,j^ | 0.996 ± 0.004 (30) | 1.000 ± 0.000 (30) | 1.000 ± 0.000 (30) | 0.995 ± 0.005 (27) | 0.979 ± 0.012 (30)

Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05.

PND = postnatal day.

^a^ One litter from the 10,000 ppm group was removed from indicated endpoints due to unclear counts.

^b^ Each exposed group was compared to the vehicle control group with the Shirley test when a trend was present (p ≤ 0.01 from the Jonckheere trend test) or with the Dunn test when no trend was present.

^c^ Data are presented as mean ± standard error (number of litters).

^d^ Litters in which the male/female pup counts were inconsistent between PND 1 and PND 4 were excluded from the male/female-specific endpoints.

^e^ Litters that had differing total counts on PND 1 and PND 4 were not included.

^f^ [100 × (number of live males in exposure group)/(number of live males and females in exposure group)](number of pups).

^g^ No statistical analysis performed on this endpoint.

^h^ Total number of dead pups in exposure group (number of litters contributing dead pups).

^i^ Survival/litter: Number of pups prestandardization on PND 4/total live pups on PND 1.

^j^ Survival/litter: Number of live pups on PND 28/number of live pups poststandardization on PND 4.

Table 21 Summary of Preweaning F_1_ Male and Female Rat Pup Mean Body Weights Following Perinatal Exposure to Tris(chloropropyl) Phosphate

Parameter | 0 ppm | 2,500 ppm | 5,000 ppm | 10,000 ppm | 20,000 ppm
Male (g)
PND 1^a,b,c^ | 7.31 ± 0.10 (27) | 7.45 ± 0.10 (32) | 7.40 ± 0.09 (34) | 7.54 ± 0.12 (29) | 7.30 ± 0.19 (33)
PND 4^d,e,f,g^ | 10.64 ± 0.14** (204/30) | 10.73 ± 0.14 (192/30) | 10.83 ± 0.16 (194/33) | 10.31 ± 0.16 (204/32) | 9.85 ± 0.16** (210/33)
PND 7^f,g,h^ | 16.30 ± 0.28** (122/30) | 16.55 ± 0.29 (120/30) | 16.25 ± 0.29 (120/30) | 15.89 ± 0.29 (110/27) | 14.42 ± 0.43** (120/30)
PND 14^f,g,h^ | 33.80 ± 0.36** (122/30) | 33.64 ± 0.39 (120/30) | 32.88 ± 0.36 (120/30) | 31.77 ± 0.48** (110/27) | 27.10 ± 0.60** (118/30)
PND 21^f,g,h^ | 56.10 ± 0.70** (122/30) | 52.02 ± 0.67** (120/30) | 49.60 ± 0.66** (120/30) | 46.50 ± 0.70** (110/27) | 38.67 ± 0.63** (118/30)
PND 28^f,g,h^ | 94.49 ± 0.97** (122/30) | 91.03 ± 1.01 (120/30) | 87.76 ± 1.03** (120/30) | 83.10 ± 1.12** (110/27) | 69.53 ± 1.43** (118/30)
Female (g)
PND 1^a,b,c^ | 6.84 ± 0.10 (27) | 7.11 ± 0.09 (32) | 7.06 ± 0.09 (33) | 7.29 ± 0.11* (28) | 6.89 ± 0.15 (34)
PND 4^d,e,f,g^ | 9.89 ± 0.15** (182/30) | 10.12 ± 0.15 (180/30) | 10.18 ± 0.17 (211/32) | 10.02 ± 0.12 (155/31)^i^ | 9.32 ± 0.17* (206/33)
PND 7^f,g,h^ | 15.33 ± 0.30** (118/30) | 15.73 ± 0.26 (120/30) | 15.46 ± 0.29 (120/30) | 15.24 ± 0.23 (105/27) | 13.68 ± 0.35** (117/30)
PND 14^f,g,h^ | 32.26 ± 0.40** (117/30) | 32.24 ± 0.32 (120/30) | 31.74 ± 0.37 (120/30) | 30.50 ± 0.40** (105/27) | 25.75 ± 0.52** (116/30)^i^
PND 21^f,g,h^ | 51.89 ± 0.66** (117/30) | 48.75 ± 0.60** (120/30) | 47.07 ± 0.62** (120/30) | 44.31 ± 0.56** (105/27) | 36.32 ± 0.52** (117/30)
PND 28^f,g,h^ | 84.50 ± 0.92** (117/30) | 81.69 ± 0.85 (120/30) | 79.37 ± 0.97** (120/30) | 75.98 ± 0.82** (105/27) | 62.59 ± 1.17** (117/30)
Male and Female (g)
PND 1^a,b,c^ | 7.07 ± 0.08 (30) | 7.26 ± 0.09 (33) | 7.31 ± 0.11 (35) | 7.40 ± 0.10 (32) | 7.09 ± 0.16 (34)
PND 4^d,e,f,g^ | 10.30 ± 0.14** (386/30) | 10.44 ± 0.14 (372/30) | 10.52 ± 0.16 (405/33) | 10.16 ± 0.14 (359/32)^i^ | 9.60 ± 0.16** (416/33)
PND 7^f,g,h^ | 15.82 ± 0.28** (240/30) | 16.14 ± 0.26 (240/30) | 15.86 ± 0.28 (240/30) | 15.57 ± 0.25 (215/27) | 14.07 ± 0.38** (237/30)
PND 14^f,g,h^ | 33.05 ± 0.35** (239/30) | 32.94 ± 0.33 (240/30) | 32.31 ± 0.35 (240/30) | 31.14 ± 0.43** (215/27) | 26.46 ± 0.55** (234/30)^i^
PND 21^f,g,h^ | 54.04 ± 0.64** (239/30) | 50.38 ± 0.62** (240/30) | 48.33 ± 0.61** (240/30) | 45.43 ± 0.61** (215/27) | 37.54 ± 0.56** (235/30)
PND 28^f,g,h^ | 89.60 ± 0.89** (239/30) | 86.36 ± 0.89 (240/30) | 83.57 ± 0.94** (240/30) | 79.61 ± 0.93** (215/27) | 66.11 ± 1.27** (235/30)

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

PND = postnatal day.

^a^ Each exposed group was compared to the vehicle control group with the Williams test when a trend was present (p ≤ 0.01 from the Jonckheere trend test) or with the Dunnett test when no trend was present.

^b^ Data are presented as mean ± standard error (number of litters).

^c^ Total pup weight at PND 1 divided by number of live pups at PND 1.

^d^ PND 4 prestandardization.

^e^ Individual pup weights first adjusted for live litter size on PND 1. Litters with differing pup counts between PND 1 and PND 4 were not included in the PND 4 prestandardization weights.

^f^ Statistical analysis performed using mixed models with random litter effect for both trend and pairwise tests, using the Dunnett-Hsu adjustment for multiple comparisons.

^g^ Data are presented as the mean of the litter means ± standard error (number of pups/number of litters).

^h^ Individual pup weights first adjusted for live litter size on PND 4 poststandardization.

^i^ One female pup from the 10,000 ppm group was removed as an outlier on PND 4; one female pup from the 20,000 ppm group was removed as an outlier on PND 14.

### Two-year Study (Postweaning Phase)

Survival of F_1_ male and female rats was not adversely affected by exposure to TCPP. At study termination, survival rates for male and female rats exposed to TCPP exceeded that of their respective control group (Table 22; Figure 2). There were no exposure-related clinical observations noted during the 2-year study (Appendix H).

Table 22 Summary of Survival of Male and Female Rats in the Perinatal and Two-year Feed Study of Tris(chloropropyl) Phosphate

| 0 ppm | 2,500 ppm | 5,000 ppm | 10,000 ppm | 20,000 ppm
Male
Animals Initially in Study | 50 | 50 | 50 | 50 | 50
Moribund | 15 | 8 | 8 | 5 | 8
Natural Deaths | 10 | 8 | 8 | 8 | 11
Animals Surviving to Study Termination | 25 | 34 | 34 | 37 | 31
Percent Probability of Survival at Study Termination^a^ | 50.0 | 68.0 | 68.0 | 74.0 | 62.0
Mean Survival (Days)^b^ | 651.9 ± 14.1 | 688.5 ± 9.9 | 699.0 ± 10.1 | 681.5 ± 16.6 | 696.5 ± 9.1
Survival Analysis^c^ | p = 0.343N | p = 0.048N | p = 0.033N | p = 0.010N | p = 0.119N
Female
Animals Initially in Study | 50 | 50 | 50 | 50 | 50
Moribund | 15 | 11 | 8 | 7 | 6
Natural Deaths | 13 | 8 | 9 | 9 | 11
Animals Surviving to Study Termination | 22 | 31 | 33 | 34 | 33
Percent Probability of Survival at Study Termination | 44.0 | 62.0 | 66.0 | 68.0 | 66.0
Mean Survival (Days) | 629.2 ± 16.3 | 675.6 ± 15.3 | 679.2 ± 12.8 | 683.3 ± 15.0 | 677.2 ± 12.1
Survival Analysis | p = 0.076N | p = 0.057N | p = 0.023N | p = 0.011N | p = 0.026N

^a^ Kaplan-Meier determinations.

^b^ Mean of litter means of all deaths (uncensored, censored, and study termination) ± standard error.

^c^ The result of the Cox proportional hazards trend test is in the vehicle control group column, and the results of the Cox proportional hazards pairwise comparisons to the vehicle control group are in the exposed group columns. A negative trend or lower mortality in an exposure group is indicated by N.

Figure 2

Kaplan-Meier Survival Curves for Male and Female Rats Exposed to Tris(chloropropyl) Phosphate in Feed for Two Years

Survival curves are shown for (A) males and (B) females.

At the start of the 2-year exposure phase, mean body weights of male and female rats in the 20,000 ppm group were approximately 75% of control group values (Table 23, Table 24; Figure 3). Over the course of the study, this gap decreased for male rats and the terminal mean body weight of the 20,000 ppm group was within 8% of that of the control group. Female rats in the 20,000 ppm group also recovered, to some degree, but their mean body weight over the course of the study fluctuated between 79% and 89% of that of the control group; their terminal mean body weight was 17% lower than that of the control group (Table 24; Figure 3). The lower weights were interpreted to be the result of lower body weight gains rather than body weight loss during the exposure period. Although mean body weights for male and female rats fluctuated over the course of the study in the lower exposed groups, mean body weights remained within 10% of the control groups during the majority of time intervals. Overall, mean body weights of female rats were more affected by TCPP exposure than those of male rats.

Table 23 Summary of Survival and Mean Body Weights of Male Rats in the Perinatal and Two-year Feed Study of Tris(chloropropyl) Phosphate

Study Day^a^ | 0 ppm | | 2,500 ppm | | | 5,000 ppm | | | 10,000 ppm | | | 20,000 ppm
Study Day^a^ | Av. Wt. (g)^b^ | No. of Litters | Av. Wt. (g) | Wt. (% of Controls) | No. of Litters | Av. Wt. (g) | Wt. (% of Controls) | No. of Litters | Av. Wt. (g) | Wt. (% of Controls) | No. of Litters | Av. Wt. (g) | Wt. (% of Controls) | No. of Litters
1 | 96.7 | 25 | 92.6 | 95.8 | 25 | 90.3 | 93.4 | 25 | 86.6 | 89.6 | 25 | 72.3 | 74.7 | 25
8 | 142.2 | 25 | 138.6 | 97.5 | 25 | 135.3 | 95.2 | 25 | 129.6 | 91.2 | 25 | 105.6 | 74.3 | 25
15 | 189.7 | 25 | 186.6 | 98.4 | 25 | 181.2 | 95.5 | 25 | 175.9 | 92.8 | 25 | 140.8 | 74.2 | 25
22 | 238.6 | 25 | 232.3 | 97.3 | 25 | 226.8 | 95.1 | 25 | 218.2 | 91.4 | 25 | 178.7 | 74.9 | 25
29 | 281.7 | 25 | 274.8 | 97.6 | 25 | 269.1 | 95.5 | 25 | 260.2 | 92.4 | 25 | 215.6 | 76.5 | 25
36 | 314.1 | 25 | 307.4 | 97.9 | 25 | 298.0 | 94.9 | 25 | 291.6 | 92.8 | 25 | 245.3 | 78.1 | 25
43 | 339.6 | 25 | 332.1 | 97.8 | 25 | 323.7 | 95.3 | 25 | 317.9 | 93.6 | 25 | 270.3 | 79.6 | 25
50 | 356.8 | 25 | 354.6 | 99.4 | 25 | 344.6 | 96.6 | 25 | 333.1 | 93.4 | 25 | 287.3 | 80.5 | 25
57 | 373.8 | 25 | 369.5 | 98.8 | 25 | 359.6 | 96.2 | 25 | 348.9 | 93.3 | 25 | 300.5 | 80.4 | 25
64 | 386.0 | 25 | 382.8 | 99.2 | 25 | 374.0 | 96.9 | 25 | 363.7 | 94.2 | 25 | 313.3 | 81.2 | 25
71 | 386.6 | 25 | 389.8 | 100.8 | 25 | 381.4 | 98.7 | 25 | 366.8 | 94.9 | 25 | 322.0 | 83.3 | 25
78 | 395.6 | 25 | 399.6 | 101.0 | 25 | 388.9 | 98.3 | 25 | 377.6 | 95.5 | 25 | 329.6 | 83.3 | 25
85 | 410.4 | 25 | 408.7 | 99.6 | 25 | 395.9 | 96.5 | 25 | 387.0 | 94.3 | 25 | 337.3 | 82.2 | 25
92 | 421.5 | 25 | 419.3 | 99.5 | 25 | 403.4 | 95.7 | 25 | 397.1 | 94.2 | 25 | 348.4 | 82.6 | 25
120 | 446.4 | 25 | 444.6 | 99.6 | 25 | 434.9 | 97.4 | 25 | 426.1 | 95.5 | 25 | 376.4 | 84.3 | 25
148 | 469.4 | 25 | 461.9 | 98.4 | 25 | 448.8 | 95.6 | 25 | 442.0 | 94.2 | 25 | 394.6 | 84.1 | 25
176 | 481.1 | 25 | 475.9 | 98.9 | 25 | 463.4 | 96.3 | 25 | 452.5 | 94.0 | 25 | 410.4 | 85.3 | 25
204 | 487.0 | 25 | 492.3 | 101.1 | 25 | 476.9 | 97.9 | 25 | 471.5 | 96.8 | 25 | 422.0 | 86.7 | 25
232 | 505.2 | 25 | 508.2 | 100.6 | 25 | 487.0 | 96.4 | 25 | 485.6 | 96.1 | 25 | 432.2 | 85.5 | 25
260 | 518.3 | 25 | 520.3 | 100.4 | 25 | 503.5 | 97.2 | 25 | 503.9 | 97.2 | 25 | 450.6 | 86.9 | 25
288 | 531.8 | 25 | 537.5 | 101.1 | 25 | 519.8 | 97.7 | 25 | 514.0 | 96.7 | 25 | 460.7 | 86.6 | 25
316 | 538.6 | 25 | 545.1 | 101.2 | 25 | 526.7 | 97.8 | 25 | 522.3 | 97.0 | 25 | 466.3 | 86.6 | 25
344 | 549.2 | 25 | 556.7 | 101.4 | 25 | 540.0 | 98.3 | 25 | 535.1 | 97.4 | 25 | 476.0 | 86.7 | 25
372 | 558.4 | 25 | 562.9 | 100.8 | 25 | 540.3 | 96.8 | 25 | 537.0 | 96.2 | 25 | 480.8 | 86.1 | 25
400 | 569.2 | 25 | 575.7 | 101.1 | 25 | 550.8 | 96.8 | 25 | 543.2 | 95.4 | 25 | 489.2 | 85.9 | 25
428 | 566.2 | 25 | 577.6 | 102.0 | 25 | 556.5 | 98.3 | 25 | 553.7 | 97.8 | 25 | 488.4 | 86.3 | 25
456 | 574.9 | 25 | 584.2 | 101.6 | 25 | 562.2 | 97.8 | 25 | 558.3 | 97.1 | 25 | 500.1 | 87.0 | 25
484 | 580.6 | 25 | 590.4 | 101.7 | 25 | 570.3 | 98.2 | 25 | 565.7 | 97.4 | 25 | 505.3 | 87.0 | 25
512 | 584.4 | 25 | 593.1 | 101.5 | 25 | 573.5 | 98.1 | 25 | 570.6 | 97.6 | 25 | 510.8 | 87.4 | 25
540 | 581.7 | 25 | 596.5 | 102.5 | 25 | 573.4 | 98.6 | 25 | 570.8 | 98.1 | 25 | 513.0 | 88.2 | 25
568 | 584.6 | 25 | 595.6 | 101.9 | 25 | 570.3 | 97.6 | 25 | 567.5 | 97.1 | 25 | 508.8 | 87.0 | 25
596 | 584.0 | 25 | 587.2 | 100.5 | 25 | 570.5 | 97.7 | 25 | 569.3 | 97.5 | 25 | 518.0 | 88.7 | 25
624 | 578.1 | 24 | 586.9 | 101.5 | 25 | 571.3 | 98.8 | 25 | 559.0 | 96.7 | 25 | 519.3 | 89.8 | 25
652 | 565.7 | 23 | 587.6 | 103.9 | 25 | 561.3 | 99.2 | 25 | 568.2 | 100.5 | 25 | 520.6 | 92.0 | 23
680 | 585.1 | 22 | 585.2 | 100.0 | 25 | 565.0 | 96.6 | 25 | 564.4 | 96.5 | 25 | 523.1 | 89.4 | 23
708 | 573.3 | 21 | 572.2 | 99.8 | 25 | 559.3 | 97.6 | 25 | 551.5 | 96.2 | 25 | 525.9 | 91.7 | 23
EOS | 574.4 | 20 | 570.7 | 99.4 | 25 | 557.4 | 97.0 | 23 | 544.6 | 94.8 | 24 | 529.2 | 92.1 | 23

No trend or pairwise statistical tests were performed on these data.

No. of litters = number of litters represented in weight average; EOS = end of study.

^a^ Study day 1 is the day animals were placed on study after pups were weaned.

^b^ Average weights shown are means of litter means.

Table 24 Summary of Survival and Mean Body Weights of Female Rats in the Perinatal and Two-year Feed Study of Tris(chloropropyl) Phosphate

Study Day^a^ | 0 ppm | | 2,500 ppm | | | 5,000 ppm | | | 10,000 ppm | | | 20,000 ppm
Study Day^a^ | Av. Wt. (g)^b^ | No. of Litters | Av. Wt. (g) | Wt. (% of Controls) | No. of Litters | Av. Wt. (g) | Wt. (% of Controls) | No. of Litters | Av. Wt. (g) | Wt. (% of Controls) | No. of Litters | Av. Wt. (g) | Wt. (% of Controls) | No. of Litters
1 | 89.3 | 25 | 87.7 | 98.2 | 25 | 84.0 | 94.0 | 25 | 82.2 | 92.1 | 25 | 67.8 | 75.9 | 25
8 | 123.6 | 25 | 123.7 | 100.1 | 25 | 118.1 | 95.5 | 25 | 117.0 | 94.6 | 25 | 98.2 | 79.4 | 25
15 | 149.9 | 25 | 152.7 | 101.9 | 25 | 146.0 | 97.4 | 25 | 143.7 | 95.9 | 25 | 122.4 | 81.7 | 25
22 | 170.5 | 25 | 171.8 | 100.8 | 25 | 165.3 | 97.0 | 25 | 164.2 | 96.3 | 25 | 139.6 | 81.9 | 25
29 | 188.1 | 25 | 188.7 | 100.3 | 25 | 179.1 | 95.2 | 25 | 182.1 | 96.8 | 25 | 161.4 | 85.8 | 25
36 | 202.7 | 25 | 202.3 | 99.8 | 25 | 194.4 | 95.9 | 25 | 194.4 | 95.9 | 25 | 175.2 | 86.5 | 25
43 | 213.4 | 25 | 211.6 | 99.2 | 25 | 204.9 | 96.0 | 25 | 204.1 | 95.7 | 25 | 183.9 | 86.2 | 25
50 | 222.8 | 25 | 220.1 | 98.8 | 25 | 214.6 | 96.3 | 25 | 213.6 | 95.9 | 25 | 192.1 | 86.3 | 25
57 | 233.4 | 25 | 230.6 | 98.8 | 25 | 223.9 | 95.9 | 25 | 220.8 | 94.6 | 25 | 201.5 | 86.4 | 25
64 | 236.8 | 25 | 234.1 | 98.9 | 25 | 229.1 | 96.8 | 25 | 225.8 | 95.4 | 25 | 205.7 | 86.9 | 25
71 | 241.0 | 25 | 238.4 | 98.9 | 25 | 232.3 | 96.4 | 25 | 230.2 | 95.5 | 25 | 212.8 | 88.3 | 25
78 | 244.3 | 25 | 241.4 | 98.8 | 25 | 233.5 | 95.6 | 25 | 229.0 | 93.7 | 25 | 209.5 | 85.7 | 25
85 | 250.1 | 25 | 248.6 | 99.4 | 25 | 240.7 | 96.2 | 25 | 236.1 | 94.4 | 25 | 215.8 | 86.3 | 25
92 | 256.6 | 25 | 250.8 | 97.7 | 25 | 247.7 | 96.5 | 25 | 241.2 | 94.0 | 25 | 220.9 | 86.1 | 25
120 | 268.6 | 25 | 263.4 | 98.0 | 25 | 257.4 | 95.8 | 25 | 252.1 | 93.8 | 25 | 232.4 | 86.5 | 25
148 | 276.6 | 25 | 266.5 | 96.3 | 25 | 264.1 | 95.5 | 25 | 258.7 | 93.5 | 25 | 243.0 | 87.9 | 25
176 | 283.0 | 25 | 273.9 | 96.8 | 25 | 268.8 | 95.0 | 25 | 263.7 | 93.2 | 25 | 247.4 | 87.4 | 25
204 | 291.8 | 25 | 281.3 | 96.4 | 25 | 279.3 | 95.7 | 25 | 271.8 | 93.2 | 25 | 253.5 | 86.9 | 25
232 | 293.1 | 25 | 289.1 | 98.6 | 25 | 281.4 | 96.0 | 25 | 273.8 | 93.4 | 25 | 261.3 | 89.1 | 25
260 | 306.4 | 25 | 293.4 | 95.8 | 25 | 284.6 | 92.9 | 25 | 279.8 | 91.3 | 25 | 264.2 | 86.2 | 25
288 | 309.5 | 25 | 296.2 | 95.7 | 25 | 291.0 | 94.0 | 25 | 283.6 | 91.6 | 25 | 268.0 | 86.6 | 25
316 | 314.8 | 25 | 302.7 | 96.2 | 25 | 292.6 | 92.9 | 25 | 286.2 | 90.9 | 25 | 273.8 | 87.0 | 25
344 | 319.6 | 25 | 306.6 | 95.9 | 25 | 298.0 | 93.2 | 25 | 288.7 | 90.3 | 25 | 273.6 | 85.6 | 25
372 | 319.0 | 25 | 312.0 | 97.8 | 25 | 299.2 | 93.8 | 25 | 291.1 | 91.3 | 25 | 275.4 | 86.3 | 25
400 | 327.8 | 25 | 311.3 | 95.0 | 25 | 300.7 | 91.7 | 25 | 293.8 | 89.6 | 25 | 278.2 | 84.9 | 25
428 | 338.9 | 25 | 318.4 | 94.0 | 25 | 311.1 | 91.8 | 25 | 297.0 | 87.6 | 25 | 281.1 | 83.0 | 25
456 | 341.7 | 25 | 322.4 | 94.4 | 25 | 313.8 | 91.8 | 25 | 299.4 | 87.6 | 25 | 282.1 | 82.6 | 25
484 | 347.3 | 25 | 328.8 | 94.7 | 25 | 320.5 | 92.3 | 25 | 301.9 | 86.9 | 25 | 284.7 | 82.0 | 25
512 | 355.4 | 25 | 335.7 | 94.5 | 25 | 322.3 | 90.7 | 25 | 305.7 | 86.0 | 25 | 286.8 | 80.7 | 25
540 | 358.0 | 25 | 340.3 | 95.1 | 25 | 325.0 | 90.8 | 25 | 307.4 | 85.9 | 25 | 289.8 | 81.0 | 25
568 | 369.0 | 24 | 340.5 | 92.3 | 25 | 327.4 | 88.7 | 25 | 306.8 | 83.1 | 25 | 294.2 | 79.7 | 25
596 | 372.0 | 22 | 342.3 | 92.0 | 24 | 329.0 | 88.4 | 25 | 308.5 | 82.9 | 25 | 293.0 | 78.8 | 24
624 | 377.3 | 22 | 344.6 | 91.3 | 24 | 336.4 | 89.2 | 25 | 311.4 | 82.5 | 25 | 298.6 | 79.1 | 24
652 | 366.1 | 21 | 338.9 | 92.6 | 22 | 339.1 | 92.6 | 25 | 316.5 | 86.5 | 25 | 302.6 | 82.6 | 24
680 | 377.8 | 19 | 340.4 | 90.1 | 21 | 336.1 | 89.0 | 24 | 318.3 | 84.3 | 24 | 298.4 | 79.0 | 23
708 | 378.9 | 19 | 341.3 | 90.1 | 20 | 345.0 | 91.0 | 24 | 325.3 | 85.9 | 24 | 300.7 | 79.4 | 23
EOS | 371.4 | 17 | 342.8 | 92.3 | 19 | 353.7 | 95.2 | 24 | 326.5 | 87.9 | 21 | 309.1 | 83.2 | 23

No trend or pairwise statistical tests were performed on these data.

No. of litters = number of litters represented in weight average; EOS = end of study.

^a^ Study day 1 is the day animals were placed on study after pups were weaned.

^b^ Average weights shown are means of litter means.

Figure 3

Growth Curves for Male and Female Rats in the Perinatal and Two-year Feed Study of Tris(chloropropyl) Phosphate

Growth curves are shown for (A) males and (B) females.

In general, feed consumption by male and female rats in the 20,000 ppm TCPP-exposed groups was slightly lower (15% for males; 4% for females) than that of the respective control groups during the first week of the study (Table 25, Table 26; Appendix H). At study termination (week 102), feed consumption by TCPP-exposed male and female rats in the 20,000 ppm group was approximately 17% and 27% lower, respectively, than that of the control groups (Table 25, Table 26). All other TCPP-exposed male and female rats (2,500, 5,000, and 10,000 ppm groups) were comparable (between 1% and 13%) to that of the control groups at study termination (Table 25, Table 26). Daily TCPP intakes, based on weekly body weight and feed consumption averages (Appendix H), were estimated to be 141, 294, 626, and 1,155 mg/kg/day for male rats in the 2,500, 5,000, 10,000, and 20,000 ppm groups, respectively, over the 2-year period. For female rats, TCPP intakes, based on weekly body weight and feed consumption averages (Appendix H), were estimated to be 156, 323, 674, and 1,295 mg/kg/day in the 2,500, 5,000, 10,000, and 20,000 ppm groups, respectively, over the 2-year period. Table 25 and Table 26 highlight feed consumption (i.e., feed [g/day]) and estimated TCPP intake (i.e., dose [mg/kg/day]) at select time points. In general, the estimated TCPP intake was proportional to the twofold increase in the respective TCPP concentration in dosed feed for both male and female rats. Further, the doses of TCPP consumed by male rats relative to female rats, in mg/kg/day, were similar for a given concentration of TCPP in feed.

Table 25 Summary of Feed and Tris(chloropropyl) Phosphate Consumption of Male Rats in the Perinatal and Two-year Tris(chloropropyl) Phosphate Study

Week | 0 ppm | 2,500 ppm | | 5,000 pm | | 10,000 ppm | | 20,000 ppm
Week | Feed (g/day)^a^ | Feed (g/day) | Dose (mg/kg/day)^b^ | Feed (g/day) | Dose (mg/kg/day) | Feed (g/day) | Dose (mg/kg/day) | Feed (g/day) | Dose (mg/kg/day)
1 | 13.9 | 14.1 | 380.7 | 14.2 | 786.5 | 14.0 | 1,617.2 | 11.8 | 3,266.3
13 | 29.9 | 28.8 | 176.2 | 29.3 | 370.1 | 31.2 | 806.1 | 30.3 | 1,796.6
54 | 29.0 | 28.2 | 125.2 | 27.8 | 257.5 | 31.0 | 575.1 | 22.6 | 940.1
102 | 27.1 | 29.9 | 131.0 | 27.5 | 246.9 | 30.5 | 557.1 | 22.4 | 855.0

No trend or pairwise statistical tests were performed on these data.

^a^ Grams of feed consumed/animal/day.

^b^ Milligrams of tris(chloropropyl) phosphate consumed/kilogram body weight/day.

Table 26 Summary of Feed and Tris(chloropropyl) Phosphate Consumption of Female Rats in the Perinatal and Two-year Tris(chloropropyl) Phosphate Study

Week | 0 ppm | 2,500 ppm | | 5,000 ppm | | 10,000 ppm | | 20,000 ppm
Week | Feed (g/day)^a^ | Feed (g/day) | Dose (mg/kg/day)^b^ | Feed (g/day) | Dose (mg/kg/day) | Feed (g/day) | Dose (mg/kg/day) | Feed (g/day) | Dose (mg/kg/day)
1 | 12.2 | 13.2 | 376.2 | 12.0 | 714.4 | 12.5 | 1,520.5 | 11.7 | 3,452.8
13 | 18.2 | 19.5 | 196.1 | 18.6 | 386.4 | 19.2 | 813.3 | 21.3 | 1,974.3
54 | 17.7 | 17.8 | 142.8 | 17.3 | 289.2 | 18.5 | 633.1 | 14.8 | 1,075.5
102 | 22.9 | 21.5 | 156.4 | 23.8 | 346.6 | 23.8 | 742.0 | 16.8 | 1,109.2

No trend or pairwise statistical tests were performed on these data.

^a^ Grams of feed consumed/animal/day.

^b^ Milligrams of tris(chloropropyl) phosphate consumed/kilogram body weight/day.

#### Histopathology

This section describes the statistically significant or biologically noteworthy changes in the incidence of neoplasms and/or nonneoplastic lesions of the liver, uterus, small intestine, testis, adrenal cortex, kidney, and ovary.

Liver: In male rats in the 10,000 and 20,000 ppm groups, the incidences of hepatocellular adenomas were higher than in control rats. In addition, the incidences of hepatocellular carcinomas also were higher in the 5,000, 10,000, and 20,000 ppm groups. The higher incidences of hepatocellular adenoma or carcinoma (combined) showed a positive trend with exposure concentration but lacked significance in pairwise tests when compared to the control group (Table 27). Nonneoplastic lesions, such as altered hepatic foci (basophilic, eosinophilic, and mixed cell), exhibited positive trends with increasing exposure concentration. In particular, the increased incidences in the 10,000 (basophilic only) and 20,000 ppm groups were significant by pairwise comparisons with the control group. There were higher incidences of biliary hyperplasia in all exposed groups (significantly increased at 2,500 and 20,000 ppm) compared to the control group, but the severity grade was minimal (Table 27). In female rats, the incidences of hepatocellular neoplasms were lower than in male rats. There were slightly higher incidences of hepatocellular adenomas in the 2,500, 10,000, and 20,000 ppm females than in the control group, but these incidences were not significant (Table 27). There were no incidences of hepatocellular carcinomas in any female exposure group. The incidences of altered hepatic foci (basophilic, eosinophilic, and mixed cell) increased with exposure concentration, but pairwise significance was achieved only with eosinophilic foci in the 10,000 and 20,000 ppm groups. There were higher incidences of biliary hyperplasia, which were statistically significant by pairwise comparison, in the 2,500, 5,000, and 10,000 ppm exposed females, but the severity grade was minimal. Interestingly, in female rats, there were also significantly increased incidences of bile duct cysts in the top three exposed groups compared to the control group. In addition, in both male and female rats, there was a significantly increased incidence of pigment in the 20,000 ppm group, but severity was minimal (Table 27).

Table 27 Incidences of Neoplastic and Nonneoplastic Lesions of the Liver in Male and Female Rats in the Perinatal and Two-year Feed Study of Tris(chloropropyl) Phosphate

| 0 ppm | 2,500 ppm | 5,000 ppm | 10,000 ppm | 20,000 ppm
Male
n ^a^ | 50 | 50 | 50 | 50 | 49
Basophilic Focus^b^ | 1** | 1 | 2 | 9* | 11*
Eosinophilic Focus | 3** | 5 | 3 | 5 | 13*
Mixed-cell Focus | 1* | 2 | 4 | 1 | 8*
Pigment | 0** | 0 | 0 | 1 (1.0)^c^ | 22** (1.1)
Bile Duct, Hyperplasia | 12** (1.2) | 23* (1.0) | 17 (1.0) | 19 (1.0) | 29** (1.0)
Hepatocellular Adenoma (Includes Multiple)^d^
Overall rate^e^ | 1/50 (2%) | 0/50 (0%) | 0/50 (0%) | 5/50 (10%) | 3/49 (6%)
Rate/litters^f^ | 1/25 (4%) | 0/25 (0%) | 0/25 (0%) | 4/25 (16%) | 3/25 (12%)
Adjusted rate^g^ | 2.6% | 0% | 0% | 11.3% | 6.8%
Terminal rate^h^ | 1/25 (4%) | 0/34 (0%) | 0/34 (0%) | 5/37 (4%) | 1/31 (3%)
First incidence (days) | 729 (T) | –^i^ | – | 729 (T) | 676
Rao-Scott-adjusted Poly-3 test^j^ | p = 0.099 | p = 0.575N | p = 0.575N | p = 0.220 | p = 0.433
Hepatocellular Carcinoma^k^
Overall rate | 0/50 (0%) | 0/50 (0%) | 1/50 (2%) | 3/50 (6%) | 3/49 (6%)
Rate/litters | 0/25 (0%) | 0/25 (0%) | 1/25 (4%) | 3/25 (12%) | 3/25 (12%)
Adjusted rate | 0% | 0% | 2.2% | 6.8% | 6.8%
Terminal rate | 0/25 (0%) | 0/34 (0%) | 1/34 (3%) | 2/37 (5%) | 2/31 (7%)
First incidence (days) | – | – | 729 (T) | 691 | 682
Rao-Scott-adjusted Poly-3 test | p = 0.051 | – | p = 0.574 | p = 0.201 | p = 0.200
Hepatocellular Adenoma or Carcinoma (Combined)^l^
Overall rate | 1/50 (2%) | 0/50 (0%) | 1/50 (2%) | 7/50 (14%) | 6/49 (12%)
Rate/litters | 1/25 (4%) | 0/25 (0%) | 1/25 (4%) | 5/25 (20%) | 6/25 (24%)
Adjusted rate | 2.6% | 0% | 2.2% | 15.8% | 13.5%
Terminal rate | 1/25 (4%) | 0/34 (0%) | 1/34 (3%) | 6/37 (16%) | 3/31 (10%)
First incidence (days) | 729 (T) | – | 729 (T) | 691 | 676
Rao-Scott-adjusted Poly-3 test | p = 0.013 | p = 0.564N | p = 0.741N | p = 0.105 | p = 0.152
Female
n | 50 | 50 | 50 | 50 | 50
Basophilic Focus | 5 | 7 | 9 | 8 | 10
Eosinophilic Focus | 5** | 2 | 13 | 18* | 25**
Mixed-cell Focus | 2** | 0 | 1 | 1 | 7
Pigment | 0** | 0 | 0 | 3 (1.3) | 23** (1.0)
Bile Duct, Cyst | 1** | 6 | 12** | 19** | 21**
Bile Duct, Hyperplasia | 7 (1.0) | 21** (1.0) | 24** (1.0) | 29** (1.1) | 11 (1.0)
Hepatocellular Adenoma (Includes Multiple)^m^
Overall rate | 1/50 (2%) | 3/50 (6%) | 0/50 (0%) | 3/50 (6%) | 3/50 (6%)
Rate/litters | 1/25 (4%) | 3/25 (12%) | 0/25 (0%) | 3/25 (12%) | 3/25 (12%)
Adjusted rate | 2.8% | 7.1% | 0% | 6.9% | 7.2%
Terminal rate | 0/22 (0%) | 2/31 (7%) | 0/33 (0%) | 3/34 (9%) | 3/33 (9%)
First incidence (days) | 630 | 546 | – | 731 (T) | 731 (T)
Rao-Scott-adjusted Poly-3 test | p = 0.266 | p = 0.373 | p = 0.462N | p = 0.386 | p = 0.368
Hepatocellular Carcinoma^n^ | 0/50 | 0/50 | 0/50 | 0/50 | 0/50
Hepatocellular Adenoma or Carcinoma (Combined)^o^
Overall rate | 1/50 (2%) | 3/50 (6%) | 0/50 (0%) | 3/50 (6%) | 3/50 (6%)
Rate/litters | 1/25 (4%) | 3/25 (12%) | 0/25 (0%) | 3/25 (12%) | 3/25 (12%)
Adjusted rate | 2.8% | 7.1% | 0% | 6.9% | 7.2%
Terminal rate | 0/22 (0%) | 2/31 (7%) | 0/33 (0%) | 3/34 (9%) | 3/33 (9%)
First incidence (days) | 630 | 546 | – | 731 (T) | 731 (T)
Rao-Scott-adjusted Poly-3 test | p = 0.266 | p = 0.373 | p = 0.462N | p = 0.386 | p = 0.368

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant (p ≤ 0.05) from the control group by the Rao-Scott-adjusted Poly-3 test; **p ≤ 0.01.

(T) = terminal euthanasia.

^a^ Number of animals with tissue examined microscopically.

^b^ Number of animals with lesion.

^c^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

^d^ Historical control incidence for perinatal and 2-year feed studies (mean ± standard deviation): 1/249 (0.4% ± 0.89%); range: 0% to 2%; all routes (mean ± standard deviation): 3/639 (0.5% ± 0.9%); range: 0% to 2%.

^e^ Number of animals with neoplasm/number of animals necropsied.

^f^ Number of litters with neoplasm-bearing animals/number of litters examined at site.

^g^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^h^ Observed incidence at terminal euthanasia.

^i^ Not applicable; no neoplasms in group.

^j^ Beneath the control incidence is the p value associated with the trend test. Beneath the exposed group incidence is the p value corresponding to pairwise comparisons between the control group and that exposed group. The Rao-Scott test adjusts the Poly-3 test (which accounts for differential mortality in animals that do not reach study termination) for within-litter correlation. A negative trend or a lower incidence in an exposure group is indicated by N.

^k^ Historical control incidence for perinatal and 2-year feed studies: 2/249 (0.81% ± 1.1%); range: 0% to 2%; all routes: 2/639 (0.34% ± 0.79%); range: 0% to 2%.

^l^ Historical control incidence for perinatal and 2-year feed studies: 3/249 (1.21% ± 1.1%); range: 0% to 2%; all routes: 5/639 (0.84% ± 1.03%); range: 0% to 2%.

^m^ Historical control incidence for perinatal and 2-year feed studies: 4/249 (1.61% ± 1.68%); range: 0% to 4%; all routes: 20/639 (2.82% ± 2.28%); range: 0% to 8%.

^n^ Historical control incidence for perinatal and 2-year feed studies: 1/249 (0.4% ± 0.89%); range: 0% to 2%; all routes: 1/639 (0.17% ± 0.58%); range: 0% to 2%.

^o^ Historical control incidence for perinatal and 2-year feed studies: 5/249 (2.01% ± 2.45%); range: 0% to 6%; all routes: 21/639 (2.98% ± 2.44%); range: 0% to 8%.

Microscopically, hepatocellular adenomas were well-circumscribed expansile masses comprising irregular plates of hepatocyte cords with eosinophilic to basophilic cytoplasm, and occasionally vacuolated cytoplasm, with minimal to mild compression of the adjacent parenchyma (Figure 4). Central veins and portal areas were occasionally entrapped in hepatocellular neoplasms. Hepatocellular carcinomas were large and invasive and were composed of nodules of neoplastic hepatocytes arranged in solid, glandular, or trabecular patterns (Figure 5). These neoplasms were also associated with increased cellular atypia accompanied by a few mitoses. Occasionally, there were areas of necrosis and hemorrhage within these masses. Hepatic foci are tinctorially discrete areas of hepatocytes that blend imperceptibly into the surrounding hepatic parenchyma with no evidence of compression or invasion. In addition, the presence of pale-gold color in the cytoplasm of hepatocytes was diagnosed as pigment. Biliary hyperplasia was of minimal severity and was characterized by increased numbers (3–5) of biliary ductules of variable sizes, lined by well-differentiated low cuboidal epithelial cells in the portal areas. The bile duct cysts observed in female rats were characterized by dilated cystic spaces lined by low columnar epithelial cells. The increased incidences of minimal biliary hyperplasia and bile duct cysts are probably not related to the hepatocellular changes.

Figure 4

Representative Image of Hepatocellular Adenoma in the Liver of a Female Rat in the Perinatal and Two-year Feed Study of Tris(chloropropyl) Phosphate (H&E)

Hepatocellular adenoma is shown in the liver of a female rat exposed to 20,000 ppm tris(chloropropyl) phosphate in feed for 2 years (2.4×). The hepatocellular adenoma is characterized by sharply demarcated nodular masses compressing the surrounding hepatic parenchyma. H&E = hematoxylin and eosin stain.

Figure 5

Representative Images of Hepatocellular Carcinoma in the Liver of a Male Rat in the Perinatal and Two-year Feed Study of Tris(chloropropyl) Phosphate (H&E)

Hepatocellular carcinoma is shown in the liver of a male rat exposed to 5,000 ppm tris(chloropropyl) phosphate in feed for 2 years. (A) The carcinoma is infiltrative and effacing the hepatic architecture and is composed of neoplastic hepatocytes arranged in solid areas with no apparent trabecular or glandular morphology (0.7×). (B) A higher magnification of panel A is shown displaying solid morphology of the hepatocellular carcinoma (10×). H&E = hematoxylin and eosin stain.

Uterus: In female rats, incidences of uterine adenocarcinomas across all exposed groups were slightly higher than that of the control group but did not reach statistical significance in a pairwise test or trend analysis (Table 28). Single incidences of adenomas were observed in the 10,000 and 20,000 ppm female groups, and a significant trend was observed for the combined incidence of uterine adenomas and adenocarcinomas. Remarkably, there was a doubling in the 5,000 and 10,000 ppm groups and a tripling in the 20,000 ppm group of the adenoma and adenocarcinoma (combined) incidences. There were slightly higher incidences of atypical hyperplasia and cystic endometrial hyperplasia in the exposed groups compared to the control group, but they did not reach statistical significance. There was also a significant increase in the incidence of uterine polyps in the 2,500 ppm group and a higher, but not statistically significant, incidence in the 20,000 ppm group. There were single incidences of squamous cell carcinomas in the 10,000 and 20,000 ppm groups and a single incidence of squamous cell papilloma in the 20,000 ppm group. Incidences of squamous metaplasia in the uterus did not reach statistical significance in a pairwise test or trend analysis.

Table 28 Incidences of Neoplastic and Nonneoplastic Lesions of the Uterus in Female Rats in the Perinatal and Two-year Feed Study of Tris(chloropropyl) Phosphate

| 0 ppm | 2,500 ppm | 5,000 ppm | 10,000 ppm | 20,000 ppm
n ^a^ | 50 | 50 | 50 | 49 | 50
Cyst^b^ | 0 | 0 | 0 | 0 | 2
Endometrium, Hyperplasia, Cystic | 18 (1.8)^c^ | 27 (1.9) | 23 (1.8) | 27 (2.0) | 19 (2.2)
Hyperplasia, Atypical | 5 (1.8) | 10 (1.5) | 6 (2.0) | 13 (1.9) | 8 (2.0)
Squamous Metaplasia | 23 (1.5) | 32 (1.5) | 26 (2.0) | 26 (2.5) | 24 (1.6)
Stromal Polyp^d^
Overall rate^e^ | 5/50 (10%) | 15/50 (30%) | 6/50 (12%) | 7/49 (14%) | 13/50 (26%)
Rate/litters^f^ | 5/25 (20%) | 13/25 (52%) | 6/25 (24%) | 7/25 (28%) | 11/25 (44%)
Adjusted rate^g^ | 13.6% | 35% | 14% | 16.3% | 30.5%
Terminal rate^h^ | 2/22 (9%) | 12/31 (39%) | 5/33 (15%) | 6/34 (18%) | 11/33 (33%)
First incidence (days) | 577 | 529 | 657 | 669 | 584
Rao-Scott-adjusted Poly-3 test^i^ | p = 0.191 | p = 0.029 | p = 0.582 | p = 0.472 | p = 0.066
Squamous Cell Papilloma^j^ | 0/50 | 0/50 | 0/50 | 0/49 | 1/50 (2%)
Squamous Cell Carcinoma^k^ | 0/50 | 0/50 | 0/50 | 1/49 (2%) | 1/50 (2%)
Adenoma, Endometrium^l^ | 0/50 | 0/50 | 0/50 | 1/49 (2%) | 1/50 (2%)
Adenocarcinoma^m^
Overall rate | 3/50 (6%) | 4/50 (8%) | 6/50 (12%) | 8/49 (16%) | 8/50 (16%)
Rate/litters | 3/25 (12%) | 4/25 (16%) | 6/25 (24%) | 8/25 (32%) | 8/25 (32%)
Adjusted rate | 8.3% | 9.6% | 14.1% | 18.6% | 18.5%
Terminal rate | 1/22 (5%) | 2/31 (7%) | 3/33 (9%) | 6/34 (18%) | 4/33 (12%)
First incidence (days) | 575 | 683 | 704 | 669 | 574
Rao-Scott-adjusted Poly-3 test | p = 0.082 | p = 0.546 | p = 0.302 | p = 0.147 | p = 0.148
Adenoma or Adenocarcinoma (Combined)^n^
Overall rate | 3/50 (6%) | 4/50 (8%) | 6/50 (12%) | 8/49 (16%) | 9/50 (18%)
Rate/litters | 3/25 (12%) | 4/25 (16%) | 6/25 (24%) | 8/25 (32%) | 9/25 (36%)
Adjusted rate | 8.3% | 9.6% | 14.1% | 18.6% | 20.9%
Terminal rate | 1/22 (5%) | 2/31 (7%) | 3/33 (9%) | 6/34 (18%) | 5/33 (15%)
First incidence (days) | 575 | 683 | 704 | 669 | 574
Rao-Scott-adjusted Poly-3 test | p = 0.043 | p = 0.546 | p = 0.301 | p = 0.146 | p = 0.098

^a^ Number of animals with tissue examined microscopically.

^b^ Number of animals with lesion.

^c^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

^d^ Historical control incidence for perinatal and 2-year feed studies (mean ± standard deviation): 37/200 (18.5% ± 9.43%); range: 10% to 32%; all routes: 75/500 (15% ± 7.62%); range: 4% to 32%.

^e^ Number of animals with neoplasm/number of animals necropsied.

^f^ Number of litters with neoplasm-bearing animals/number of litters examined at site.

^g^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^h^ Observed incidence at terminal euthanasia.

^i^ Beneath the control incidence is the p value associated with the trend test. Beneath the exposed group incidence is the p value corresponding to pairwise comparisons between the control group and that exposed group. The Rao-Scott test adjusts the Poly-3 test (which accounts for differential mortality in animals that do not reach study termination) for within-litter correlation. A negative trend or a lower incidence in an exposure group is indicated by N.

^j^ Historical control incidence for perinatal and 2-year feed studies: 0/200 (0% ± 0%); range: 0% to 0%; all routes: 1/500 (0.2% ± 0.63%); range: 0% to 2%.

^k^ Historical control incidence for perinatal and 2-year feed studies: 0/200 (0% ± 0%); range: 0% to 0%; all routes: 4/500 (0.8% ± 1.4%); range: 0% to 4%.

^l^ Historical control incidence for perinatal and 2-year feed studies: 1/200 (0.5% ± 1%); range: 0% to 2%; all routes: 3/500 (0.6% ± 1.35%); range: 0% to 4%.

^m^ Historical control incidence for perinatal and 2-year feed studies: 12/200 (6% ± 3.27%); range: 2% to 10%; all routes: 27/500 (5.4% ± 2.84%); range: 2% to 10%.

^n^ Historical control incidence for perinatal and 2-year feed studies: 13/200 (6.5% ± 2.52%); range: 4% to 10%; all routes: 30/500 (6% ± 2.67%); range: 2% to 10%.

Uterine adenocarcinomas were characterized by poorly circumscribed proliferations of cuboidal to columnar epithelial cells that displayed pleomorphism and atypia (Figure 6A). The cells were arranged in papillary or glandular structures, and there was effacement of the normal parenchyma and invasion into the underlying musculature and serosa (Figure 6B). Atypical endometrial hyperplasia was characterized by clusters of enlarged glands lined by thickened, disorganized epithelium with epithelial cells displaying loss of nuclear polarity, karyomegaly, mitoses, and cellular pleomorphism (Figure 7A). Occasionally, these proliferating cells abutted or invaded into the myometrium (Figure 7B). Cystic endometrial hyperplasia was characterized by an increased number of endometrial glandular epithelial cells surrounding large open spaces (cystic); the increased endometrial epithelial cells did not lose nuclear polarity or exhibit atypia or mitoses. Adenomyosis, characterized by extension of the normal endometrial glands into myometrial layers, was occasionally observed (Figure 8). Stromal polyps were exophytic nodules that projected into the uterine lumen and were characterized by broad stalks of endometrial stroma that were covered by normal-appearing endometrial surface epithelium. The endometrial stroma contained blood vessels and occasional endometrial glands.

Figure 6

Representative Images of Adenocarcinoma in the Uterus of a Female Rat in the Perinatal and Two-year Feed Study of Tris(chloropropyl) Phosphate (H&E)

Adenocarcinoma is shown in the uterus of a female rat exposed to 2,500 ppm tris(chloropropyl) phosphate in feed for 2 years. (A) These tumors are characterized by poorly circumscribed proliferations of cuboidal to columnar epithelial cells arranged in papillary or glandular structures and invade through both the muscular tunics and the serosa (0.7×). (B) A higher magnification of panel A is shown (10×). The neoplastic endometrial glands have invaded through the muscular tunics and serosa, and are characterized by cellular atypia, karyomegaly with prominent nucleoli and occasional mitoses. H&E = hematoxylin and eosin stain.

Figure 7

Representative Images of Atypical Endometrial Hyperplasia in the Uterus of a Female Rat in the Perinatal and Two-year Feed Study of Tris(chloropropyl) Phosphate (H&E)

Atypical (endometrial) hyperplasia is shown in the uterus of a female rat exposed to 5,000 ppm tris(chloropropyl) phosphate in feed for 2 years. (A) This lesion is characterized by clusters of proliferating endometrial glands that may invade the inner myometrial layer but not the outer muscular tunic (0.6×). (B) A higher magnification of panel A is shown (10×). Clusters of proliferating endometrial glands are invading the endometrial stroma and also the inner muscular tunic but not the outer muscular layer. The proliferating endometrial glands have varying degrees of cellular atypia with prominent nucleoli and rare mitoses. H&E = hematoxylin and eosin stain.

Figure 8

Representative Image of Cystic Endometrial Hyperplasia in the Uterus of a Female Rat in the Perinatal and Two-year Feed Study of Tris(chloropropyl) Phosphate (H&E)

Cystic endometrial hyperplasia is shown in the uterus of a female rat exposed to 2,500 ppm tris(chloropropyl) phosphate in feed for 2 years (4×). This lesion is characterized by increased number of tortuous, often cystic, endometrial glands lined by a single layer of epithelial cells within the endometrial stroma. These increased endometrial epithelial cells generally do not exhibit increased atypia, or mitoses. Adenomyosis (extension of normal endometrial glands into the myometrium) is often seen in severe cases. H&E = hematoxylin and eosin stain.

Squamous cell carcinomas were characterized by poorly circumscribed proliferation of polygonal epithelial cells arranged in nests, cords, and papillary structures that occupied the uterine lumen and extended deep into the myometrium and onto the serosal surface. The neoplastic cells exhibited keratinization multifocally, cellular atypia, and mitotic figures. There was marked desmoplasia surrounding nests of squamous cells, large areas of keratinization, areas of necrosis, hemorrhage, and inflammation within the tumors. Squamous cell papilloma is characterized by exophytic proliferation of squamous cells in the form of nests, cords, and papillary fronds surrounded by stroma but the endometrium or myometrium was not invaded. The tumor mass had a broad base, multifocal keratinized squamous cells, areas of necrosis, and hemorrhage. Squamous metaplasia is characterized by multifocal replacement of the columnar to cuboidal endometrial epithelium with stratified squamous epithelial cells with varying degree of keratinization.

In addition to the neoplastic lesions discussed above, there were nonsignificant increases in neoplastic lesions in the small intestine, testis, adrenal gland, kidney, and ovary (Appendix H).

Small Intestine: In male rats, there were slightly higher incidences of adenocarcinoma in the small intestine in one rat in the 5,000 ppm group and in three rats in the 20,000 ppm group; these increases were not statistically significant in comparison to the control group (Appendix H). These neoplasms are uncommon in rats, with an approximate 2% incidence in NTP historical control animals for all routes of exposure. They are characterized by neoplastic glandular epithelium with nuclear atypia, loss of polarity, and invasion into the underlying muscular tunics. There were no incidences of these neoplasms in female rats in this study.

Testis: In male rats, there were slightly higher incidences of interstitial cell adenoma (also known as Leydig cell neoplasm) in the testis of three rats each in the 2,500, 10,000, and 20,000 ppm TCPP groups; these increases were not statistically significant in comparison to the control group (Appendix H). These neoplasms are not uncommon in rats with approximately 0%–6% and 0%–14% incidences in NTP historical control animals from experiments with exposure via feed versus all routes of exposure, respectively. These neoplasms are characterized by circumscribed masses larger than three normal seminiferous tubules that slightly compress the surrounding seminiferous tubules and are composed of uniform polyhedral neoplastic interstitial cells with abundant finely granular eosinophilic or vacuolated cytoplasm and centrally located nuclei with prominent nucleoli.

Adrenal Cortex: In female rats, there were slightly higher incidences of adenoma in the adrenal cortex in two rats each in the 10,000 and 20,000 ppm TCPP groups; these increases were not statistically significant in comparison to the control group (Appendix H). These neoplasms are uncommon in rats with an approximate 2% incidence in NTP historical control animals from all routes of exposure. These neoplasms are characterized by discrete expansile masses compressing the adjacent cortical tissue and are composed of cords, trabeculae, or solid clusters of enlarged polyhedral cells with eosinophilic, vacuolated cytoplasm, and may be accompanied by atypia and occasional mitosis. In male rats, there were single incidences in the 2,500 and 10,000 ppm groups.

Kidney: In female rats, there were renal tubule adenomas in the kidneys of two individuals in the 20,000 ppm group; the increased incidence was not statistically significant in comparison to the control group (Appendix H). These neoplasms are very rare in rats with <1% incidence in NTP historical control animals for all routes of exposure and 0% incidence in feed studies. These neoplasms are characterized by discrete expansile masses compressing the adjacent renal tubules and are composed of solid clusters of enlarged polyhedral cells with amphiphilic cytoplasm and may be accompanied by atypia and occasional mitosis. In male rats, there was a single incidence of renal tubule carcinoma in the 5,000 ppm TCPP group.

Ovary: In female rats, there were higher incidences of malignant granulosa cell neoplasms in the 2,500 ppm (one) and 5,000 ppm (three) groups and benign granulosa cell neoplasms in the 20,000 ppm group (two) (Appendix H). These neoplasms are relatively uncommon and have <2% incidence in NTP historical control animals from feed as well as from all routes of exposure. The benign granulosa cell neoplasms are composed of a discrete nodule larger than a corpus luteum and comprise >70% granulosa cell follicle-like nests and nodules intermixed with other sex cord/stromal cells. The granulosa cells are small round to fusiform, basophilic with scant eosinophilic cytoplasm, and nuclei with stippled chromatic and nucleoli. In the benign neoplasm, there is some compression and in the malignant variant, there is invasion into the adjacent parenchyma.

Other Tissues: In addition to the neoplastic findings, there were higher incidences of some nonneoplastic lesions including focal granulomatous inflammation in the lung (all exposure groups) and hyperplasia of the prostatic epithelium (5,000 and 20,000 ppm groups) in male rats and suppurative inflammation in the kidney (0 and 20,000 ppm groups) in female rats (Appendix H). However, the biological or toxicological significance of these lesions could not be determined.

## Mice

### Three-month Study

All male and female mice survived to study termination, and no clinical signs of toxicity were observed in TCPP-exposed groups (Table 29, Table 30; Appendix H). TCPP-exposed males gained less weight than did animals in the control group in an exposure concentration-dependent manner throughout the study. By study termination, mean body weights of male mice in the 2,500, 5,000, 10,000, and 20,000 ppm groups were approximately 11%, 16%, 24%, and 29% lower, respectively, than that of the control group (Table 29; Figure 9). Mean body weights for males exposed to 1,250 ppm remained within 10% of the control group throughout the study. Female mice also gained less weight than did animals in the control group, but this response was not exposure concentration dependent. By study termination, mean body weights of female mice in the 1,250, 2,500, 5,000, 10,000, and 20,000 ppm groups were approximately 12%, 7%, 3%, 9%, and 15% lower, respectively, than that of the control group (Table 30; Figure 9).

Table 29 Summary of Survival and Mean Body Weights of Male Mice in the Three-month Feed Study of Tris(chloropropyl) Phosphate

Study Day^a^ | 0 ppm | | 1,250 ppm | | | 2,500 ppm | | | 5,000 ppm | | | 10,000 ppm | | | 20,000 ppm
Study Day^a^ | Av. Wt. (g) | n | Av. Wt. (g) | Wt. (% of Controls) | n | Av. Wt. (g) | Wt. (% of Controls) | n | Av. Wt. (g) | Wt. (% of Controls) | n | Av. Wt. (g) | Wt. (% of Controls) | n | Av. Wt. (g) | Wt. (% of Controls) | n
1 | 21.3 | 10 | 21.3 | 100.1 | 10 | 21.3 | 100.4 | 10 | 21.3 | 100.2 | 10 | 21.2 | 99.7 | 10 | 21.2 | 99.8 | 10
8 | 22.2 | 10 | 22.2 | 99.9 | 10 | 22.1 | 99.6 | 10 | 21.9 | 98.6 | 10 | 21.3 | 95.9 | 10 | 20.1 | 90.7 | 10
15 | 23.3 | 10 | 23.1 | 99.4 | 10 | 22.9 | 98.5 | 10 | 22.3 | 95.8 | 10 | 21.7 | 93.1 | 10 | 20.1 | 86.5 | 10
22 | 24.0 | 10 | 24.0 | 100.3 | 10 | 23.7 | 98.9 | 10 | 23.1 | 96.3 | 10 | 22.3 | 93.0 | 10 | 21.0 | 87.7 | 10
29 | 25.0 | 10 | 24.9 | 99.6 | 10 | 24.6 | 98.4 | 10 | 23.6 | 94.6 | 10 | 22.8 | 91.1 | 10 | 21.5 | 85.9 | 10
36 | 25.4 | 10 | 25.6 | 100.7 | 10 | 25.2 | 99.1 | 10 | 24.0 | 94.4 | 10 | 22.9 | 90.3 | 10 | 21.8 | 85.9 | 10
43 | 27.1 | 10 | 26.6 | 98.2 | 10 | 25.7 | 94.7 | 10 | 24.7 | 91.1 | 10 | 23.9 | 88.1 | 10 | 22.1 | 81.8 | 10
50 | 27.8 | 10 | 27.3 | 98.5 | 10 | 26.4 | 95.1 | 10 | 25.4 | 91.5 | 10 | 24.2 | 87.2 | 10 | 22.7 | 81.9 | 10
57 | 28.9 | 10 | 28.5 | 98.5 | 10 | 27.5 | 95.0 | 10 | 25.9 | 89.6 | 10 | 24.8 | 85.7 | 10 | 23.4 | 80.8 | 10
64 | 29.6 | 10 | 28.9 | 97.7 | 10 | 27.5 | 92.9 | 10 | 26.2 | 88.6 | 10 | 25.0 | 84.4 | 10 | 23.3 | 78.8 | 10
71 | 30.9 | 10 | 29.4 | 95.2 | 10 | 27.5 | 88.9 | 10 | 26.7 | 86.6 | 10 | 24.0 | 77.8 | 10 | 23.9 | 77.4 | 10
78 | 31.5 | 10 | 29.8 | 94.7 | 10 | 28.4 | 90.3 | 10 | 26.8 | 85.1 | 10 | 25.1 | 79.8 | 10 | 24.0 | 76.3 | 10
85 | 32.4 | 10 | 30.9 | 95.4 | 10 | 29.1 | 90.0 | 10 | 27.9 | 86.1 | 10 | 25.9 | 79.9 | 10 | 25.0 | 77.2 | 10
92 | 32.6 | 10 | 31.2 | 95.5 | 10 | 29.1 | 89.1 | 10 | 27.5 | 84.3 | 10 | 25.6 | 78.4 | 10 | 24.4 | 74.8 | 10
EOS | 33.3 | 10 | 32.0 | 96.1 | 10 | 29.7 | 89.3 | 10 | 27.9 | 83.9 | 10 | 25.3 | 75.8 | 10 | 23.8 | 71.3 | 10

No trend or pairwise statistical tests were performed on these data.

EOS = end of study.

^a^ Study day 1 is the day animals were placed on study.

Table 30 Summary of Survival and Mean Body Weights of Female Mice in the Three-month Feed Study of Tris(chloropropyl) Phosphate

Study Day^a^ | 0 ppm | | 1,250 ppm | | | 2,500 ppm | | | 5,000 ppm | | | 10,000 ppm | | | 20,000 ppm
Study Day^a^ | Av. Wt. (g) | n | Av. Wt. (g) | Wt. (% of Controls) | n | Av. Wt. (g) | Wt. (% of Controls) | n | Av. Wt. (g) | Wt. (% of Controls) | n | Av. Wt. (g) | Wt. (% of Controls) | n | Av. Wt. (g) | Wt. (% of Controls) | n
1 | 17.7 | 10 | 17.3 | 98.0 | 10 | 17.6 | 99.4 | 10 | 17.4 | 98.3 | 10 | 17.3 | 97.7 | 10 | 17.3 | 98.1 | 10
8 | 17.7 | 10 | 18.0 | 101.7 | 10 | 17.9 | 101.4 | 10 | 17.3 | 98.2 | 10 | 17.2 | 97.6 | 10 | 16.0 | 90.8 | 10
15 | 18.8 | 10 | 18.8 | 100.2 | 10 | 14.6 | 77.9 | 10 | 16.6 | 88.3 | 10 | 17.7 | 94.3 | 10 | 17.3 | 92.0 | 10
22 | 19.8 | 10 | 19.5 | 98.1 | 10 | 19.0 | 95.6 | 10 | 18.6 | 93.7 | 10 | 18.0 | 90.9 | 10 | 17.7 | 89.1 | 10
29 | 20.4 | 10 | 20.4 | 100.2 | 10 | 19.7 | 96.8 | 10 | 19.5 | 95.6 | 10 | 18.6 | 91.3 | 10 | 17.8 | 87.4 | 10
36 | 20.6 | 10 | 20.6 | 100.1 | 10 | 20.2 | 98.4 | 10 | 19.9 | 96.6 | 10 | 19.0 | 92.2 | 10 | 18.1 | 88.2 | 10
43 | 21.8 | 10 | 21.7 | 99.5 | 10 | 21.6 | 99.0 | 10 | 20.8 | 95.2 | 10 | 19.9 | 91.1 | 10 | 18.8 | 86.3 | 10
50 | 21.8 | 10 | 22.4 | 102.6 | 10 | 22.0 | 100.9 | 10 | 21.4 | 98.1 | 10 | 20.1 | 92.2 | 10 | 18.8 | 86.2 | 10
57 | 22.2 | 10 | 22.8 | 103.0 | 10 | 22.0 | 99.2 | 10 | 21.5 | 96.8 | 10 | 20.5 | 92.5 | 10 | 18.8 | 84.8 | 10
64 | 23.3 | 10 | 24.1 | 103.3 | 10 | 23.2 | 99.3 | 10 | 22.2 | 95.0 | 10 | 21.1 | 90.4 | 10 | 19.8 | 84.7 | 10
71 | 24.4 | 10 | 24.7 | 101.1 | 10 | 24.0 | 98.4 | 10 | 23.1 | 94.7 | 10 | 22.1 | 90.6 | 10 | 20.4 | 83.5 | 10
78 | 23.4 | 10 | 24.9 | 106.5 | 10 | 24.5 | 104.7 | 10 | 23.1 | 98.8 | 10 | 22.2 | 94.9 | 10 | 20.5 | 87.7 | 10
85 | 24.0 | 10 | 24.7 | 102.6 | 10 | 24.0 | 99.9 | 10 | 22.8 | 94.8 | 10 | 21.7 | 90.5 | 10 | 20.5 | 85.3 | 10
92 | 24.6 | 10 | 25.3 | 102.7 | 10 | 25.0 | 101.4 | 10 | 23.4 | 94.8 | 10 | 22.2 | 90.1 | 10 | 19.9 | 80.6 | 10
EOS | 24.5 | 10 | 21.6 | 88.0 | 10 | 22.7 | 92.5 | 10 | 23.8 | 97.1 | 10 | 22.2 | 90.5 | 10 | 20.8 | 84.8 | 10

No trend or pairwise statistical tests were performed on these data.

EOS = end of study.

^a^ Study day 1 is the day animals were placed on study.

Figure 9

Growth Curves for Male and Female Mice in the Three-month Feed Study of Tris(chloropropyl) Phosphate

Growth curves are shown for (A) males and (B) females.

Feed consumption by male and female mice was typically within 10% of that of control animals (Table 31, Table 32; Appendix H). At times, consumption by mice exposed to ≥5,000 ppm TCPP was approximately 10% higher than by control groups. TCPP intakes, based on weekly averaging (Appendix H), were estimated to be 225, 473, 1,050, 2,509, and 4,446 mg/kg/day for male mice in the 1,250, 2,500, 5,000, 10,000, and 20,000 ppm groups, respectively. For female mice, TCPP intakes, based on weekly averaging (Appendix H), were estimated to be 204, 442, 924, 1,841, and 3,645 mg/kg/day in the 1,250, 2,500, 5,000, 10,000, and 20,000 ppm groups, respectively. Table 31 and Table 32 highlight feed consumption (i.e., feed [g/day]) and estimated TCPP intake (i.e., dose [mg/kg/day]) at select time points. In general, the increase in TCPP intake across groups was of similar proportion to the increase in exposure concentration across groups for both sexes.

Table 31 Summary of Feed and Tris(chloropropyl) Phosphate Consumption of Male Mice in the Three-month Feed Study

Week | 0 ppm | 1,250 ppm | | 2,500 ppm | | 5,000 ppm | | 10,000 ppm | | 20,000 ppm
Week | Feed (g/day)^a^ | Feed (g/day) | Dose (mg/kg/day)^b^ | Feed (g/day) | Dose (mg/kg/day) | Feed (g/day) | Dose (mg/kg/day) | Feed (g/day) | Dose (mg/kg/day) | Feed (g/day) | Dose (mg/kg/day)
1 | 4.0 | 4.0 | 235.0 | 4.4 | 515.5 | 5.0 | 1,174.3 | 5.1 | 2,407.9 | 3.4 | 3,207.5
4 | 4.5 | 4.7 | 244.4 | 4.9 | 516.4 | 5.5 | 1,190.5 | 5.9 | 2,645.7 | 5.0 | 4,752.9
13 | 4.5 | 4.7 | 190.2 | 4.6 | 394.8 | 4.8 | 861.5 | 5.8 | 2,242.8 | 5.1 | 4,083.3

No trend or pairwise statistical tests were performed on these data.

^a^ Grams of feed consumed/animal/day.

^b^ Milligrams of tris(chloropropyl) phosphate consumed/kilogram body weight/day.

Table 32 Summary of Feed and Tris(chloropropyl) Phosphate Consumption of Female Mice in the Three-month Feed Study

Week | 0 ppm | 1,250 ppm | | 2,500 ppm | | 5,000 ppm | | 10,000 ppm | | 20,000 ppm
Week | Feed (g/day)^a^ | Feed (g/day) | Dose (mg/kg/day)^b^ | Feed (g/day) | Dose (mg/kg/day) | Feed (g/day) | Dose (mg/kg/day) | Feed (g/day) | Dose (mg/kg/day) | Feed (g/day) | Dose (mg/kg/day)
1 | 2.7 | 3.4 | 245.4 | 3.8 | 540.7 | 3.6 | 1,036.3 | 3.4 | 1,969.9 | 3.3 | 3,808.4
4 | 3.4 | 3.5 | 224.9 | 3.5 | 461.7 | 3.5 | 941.4 | 3.1 | 1,720.3 | 2.8 | 3,171.0
13 | 3.4 | 3.3 | 167.3 | 3.8 | 395.8 | 4.1 | 900.7 | 4.6 | 2,116.9 | 4.4 | 4,294.8

No trend or pairwise statistical tests were performed on these data.

^a^ Grams of feed consumed/animal/day.

^b^ Milligrams of tris(chloropropyl) phosphate consumed/kilogram body weight/day.

At study termination, the white blood cell count and lymphocyte count were significantly decreased in 20,000 ppm male mice (Appendix H). These decreases are consistent with chronic stress of exposure, which is supported by the moderate decreases in mean body weight observed in this exposed group.^97^ All other significant hematology changes were minimal or inconsistent and not considered to be due to TCPP exposure (Appendix H).

TCPP exposure was associated with organ weight changes in the liver and kidney (Table 33). In the liver, the only significant increases in absolute weight were observed in male and female mice in the 20,000 ppm group; liver weight was increased by approximately 39% and 25% in male and female mice, respectively, at study termination. Relative liver weights were significantly increased in the 2,500, 5,000, 10,000, and 20,000 ppm male and female groups (Table 33). These liver weight changes were associated with microscopic changes (described below).

Table 33 Summary of Select Organ Weights and Organ-Weight-to-Body-Weight Ratios for Male and Female Mice in the Three-month Feed Study of Tris(chloropropyl) Phosphate^a,b^

| 0 ppm | 1,250 ppm | 2,500 ppm | 5,000 ppm | 10,000 ppm | 20,000 ppm
n | 10 | 10 | 10 | 10 | 10 | 10
Male
Terminal Body Wt. (g) | 33.3 ± 1.2** | 32.0 ± 0.7 | 29.7 ± 0.8** | 27.9 ± 0.4** | 25.3 ± 0.9** | 23.8 ± 0.8**
Liver
Absolute (g) | 1.53 ± 0.05** | 1.54 ± 0.03 | 1.52 ± 0.04 | 1.55 ± 0.02 | 1.64 ± 0.09 | 2.12 ± 0.08**
Relative (mg/g)^c^ | 46.04 ± 0.55** | 48.09 ± 0.66 | 51.26 ± 0.39** | 55.63 ± 0.59** | 64.41 ± 2.02** | 89.10 ± 1.29**
Right Kidney
Absolute (g) | 0.27 ± 0.01** | 0.26 ± 0.01 | 0.25 ± 0.01 | 0.23 ± 0.00** | 0.21 ± 0.01** | 0.21 ± 0.00**
Relative (mg/g) | 8.19 ± 0.31** | 8.06 ± 0.07 | 8.56 ± 0.20 | 8.38 ± 0.15 | 8.49 ± 0.11 | 8.68 ± 0.20
Female
Terminal Body Wt. (g) | 24.5 ± 0.3** | 21.6 ± 0.2* | 22.7 ± 0.9* | 23.8 ± 0.3* | 22.2 ± 0.4** | 20.8 ± 0.3**
Liver
Absolute (g) | 1.13 ± 0.02** | 1.04 ± 0.01 | 1.12 ± 0.07 | 1.22 ± 0.03 | 1.22 ± 0.04 | 1.41 ± 0.04**
Relative (mg/g) | 46.13 ± 0.52** | 48.12 ± 0.57 | 49.04 ± 1.31* | 51.15 ± 0.84** | 54.89 ± 0.98** | 67.72 ± 1.23**
Right Kidney
Absolute (g) | 0.16 ± 0.00** | 0.16 ± 0.00 | 0.16 ± 0.00 | 0.15 ± 0.00 | 0.15 ± 0.00 | 0.14 ± 0.00**
Relative (mg/g) | 6.45 ± 0.09 | 7.33 ± 0.11** | 7.07 ± 0.19** | 6.38 ± 0.12 | 6.91 ± 0.11 | 6.88 ± 0.12

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ Data are presented as mean ± standard error.

^b^ Statistical analysis performed by the Jonckheere (trend) and the Williams or Dunnett (pairwise) tests.

^c^ Relative organ weights (organ-weight-to-body-weight ratios) are given as mg organ weight/g body weight.

Absolute kidney weights decreased with increasing exposure concentration, with the greatest difference from the control mice reported for the 20,000 ppm groups: a 22% significant decrease in males and 13% significant decrease in females (Table 33). Relative kidney weights were generally higher in male and female mice exposed to TCPP. Some changes were significantly different from the control groups; however, they were not considered related to exposure concentration. Although microscopic changes were observed in the male kidney (described below), there is no direct link with organ weight changes.

Compared to the control groups, mean absolute heart weights in male mice exposed to 10,000 and 20,000 ppm were significantly decreased by 15%; mean absolute heart weights were significantly decreased by 19% in female mice in the 20,000 ppm group. Mean relative heart weights were significantly increased in male mice exposed to ≥5,000 ppm TCPP, but this effect did not occur in female mice. Changes in absolute or relative heart weight did not correspond with microscopic changes (Appendix H). The biological and toxicological significance of this change is unclear. Absolute testis weights in mice were significantly decreased by 8% in the 20,000 ppm group and relative testis weights were significantly increased in ≥2,500 ppm TCPP dosed groups (Appendix H). The weights of the epididymis and cauda epididymis in the 20,000 ppm group were significantly decreased by 15% and 14%, respectively. No exposure-related changes were observed in counts (spermatid or sperm), density (spermatid or sperm), or sperm motility (Appendix H). These observations are consistent with the absence of microscopic changes, and, therefore, changes in testicular and epididymal weights are considered a consequence of exposure-related lower body weight of these mice.

#### Histopathology

This section describes the statistically significant or biologically noteworthy changes in the incidence of nonneoplastic lesions of the liver and kidney.

Liver: Relative liver weights were significantly increased in all ≥2,500 ppm groups of male and female mice (Table 33). Microscopically, these increases in liver weights were associated with an increase in the incidences of hepatocellular hypertrophy; these increases were significant in the 5,000, 10,000, and 20,000 ppm male and female groups (Table 34). Depending on the severity of the lesion, the hepatocyte hypertrophy was distributed within the centrilobular to panlobular regions. In severe cases, the centrilobular hepatocytes contained intensely eosinophilic intracytoplasmic granular material. In less severe cases, these cytoplasmic tinctorial differences were not apparent.

Table 34 Incidences of Nonneoplastic Lesions of the Liver and Kidney in Male and Female Mice in the Three-month Feed Study of Tris(chloropropyl) Phosphate

| 0 ppm | 1,250 ppm | 2,500 ppm | 5,000 ppm | 10,000 ppm | 20,000 ppm
Male
Liver^a^ | 10 | 10 | 10 | 10 | 10 | 10
Hepatocyte, hypertrophy^b^ | 0** | 0 | 3 (1.0)^c^ | 6** (1.2) | 10** (2.4) | 10** (4.0)
Kidney
Renal tubule, cytoplasmic alteration | 0** | 0 | 8** (1.4) | 10** (2.3) | 10** (2.9) | 10** (3.0)
Female
Liver | 10 | 10 | 10 | 10 | 10 | 10
Hepatocyte, hypertrophy | 0** | 0 | 0 | 5** (1.0) | 10** (1.5) | 10** (3.0)

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

** Statistically significant at p ≤ 0.01 by the Poly-3 test.

^a^ Number of animals examined microscopically.

^b^ Number of animals with lesion.

^c^ Average severity grade of observed lesion in affected animals: 1 = minimal; 2 = mild; 3 = moderate; 4 = marked.

Kidney: There were significant increases in the incidences of cytoplasmic alteration in renal tubules of male mice exposed to 2,500, 5,000, 10,000, and 20,000 ppm (Table 34). Control male mice contained multiple, irregular, cytoplasmic vacuoles within the cortical renal tubular epithelial cells, whereas control female mice did not contain these vacuoles. Cytoplasmic alteration within the renal tubules of male mice was characterized by lack of cytoplasmic vacuoles in the tubular epithelial cells in the cortex.

### Exposure Concentration Selection Rationale for Two-year Study in Mice

For the 3-month exposures in mice, there was no effect at 20,000 ppm on survival or clinical signs of toxicity. However, male mice in the 10,000 and 20,000 ppm groups had lower mean body weights compared to control males, which exhibited >20% difference, whereas the female mean body weight was 15% lower in the 20,000 ppm group compared to that of the respective control group. Histopathological evidence in the liver suggested that male mice displayed a slightly higher severity than female mice to TCPP exposure. Informed by these data, 0, 1,250, 2,500, and 5,000 ppm TCPP were selected for male mice and 0, 2,500, 5,000, and 10,000 ppm TCPP were chosen for female mice in the 2-year feed study.

### Two-year Study

Survival of male and female mice was not adversely affected by exposure to TCPP (Table 35; Figure 10), and there were no exposure-related clinical observations noted during study (Appendix H).

Table 35 Summary of Survival of Male and Female Mice in the Two-year Feed Study of Tris(chloropropyl) Phosphate

| 0 ppm | 1,250 ppm | 2,500 ppm | 5,000 ppm
Male
Animals Initially in Study | 50 | 50 | 50 | 50
Moribund | 1 | 1 | 1 | 3
Natural Deaths | 11 | 5 | 7 | 4
Animals Surviving to Study Termination | 38 | 44 | 42 | 43
Percent Probability of Survival at Study Termination^a^ | 78.0 | 88.0 | 84.0 | 88.0
Mean Survival (Days)^b^ | 700.8 ± 9.5 | 715.6 ± 8.0 | 712.2 ± 7.2 | 724.6 ± 3.3
Survival Analysis^c^ | p = 0.284N | p = 0.266N | p = 0.575N | p = 0.225N
| 0 ppm | 2,500 ppm | 5,000 ppm | 10,000 ppm
Female
Animals Initially in Study | 50 | 50 | 50 | 50
Moribund | 1 | 2 | 1 | 1
Natural Deaths | 3 | 5 | 4 | 3
Animals Surviving to Study Termination | 46 | 43 | 45 | 46
Percent Probability of Survival at Study Termination | 92.0 | 86.0 | 90.0 | 92.0
Mean Survival (Days) | 725.7 ± 2.0 | 709.6 ± 9.6 | 722.5 ± 3.4 | 722.6 ± 3.2
Survival Analysis | p = 0.890N | p = 0.486 | p = 0.972 | p = 1.000

^a^ Kaplan-Meier determinations.

^b^ Mean of all deaths (uncensored, censored, and study termination) ± standard error.

^c^ The result of the Tarone trend test is in the vehicle control group column, and the results of the Cox proportional hazards pairwise comparisons to the vehicle control group are in the exposed group columns. A negative trend or lower mortality in an exposure group is indicated by N.

Figure 10

Kaplan-Meier Survival Curves for Male and Female Mice Exposed to Tris(chloropropyl) Phosphate in Feed for Two Years

Survival curves are shown for (A) males and (B) females.

Exposure concentration-related decreases in mean body weights relative to the control groups were observed in both male and female mice, although the response was greater in females. Mean body weights of male mice in the 1,250 and 2,500 ppm groups remained within 10% of the control group value over the 2-year exposure period (Table 36; Figure 11). The 5,000 ppm male mice maintained mean body weights within 10% of the control group value for approximately the first 2 months of exposure. After this time, mean body weights fluctuated between 12% and 21% of the control group value and the mean body weights of this group were 18% lower than that of the control group at study termination. Lower, exposure concentration-dependent group mean body weight gains were apparent for female mice in all TCPP-exposed groups. At study termination, mean body weights were 87%, 74%, and 62% of the control group in the 2,500, 5,000, and 10,000 ppm TCPP-exposed groups, respectively (Table 37; Figure 11). The lower mean body weights observed in mice were interpreted as the result of lower body weight gains rather than body weight loss during the exposure period. Despite the exposed female mice having lower weight gain compared to the control group, these animals displayed no adverse clinical observations or notable decreases in feed consumption (Appendix H).

Table 36 Summary of Survival and Mean Body Weights of Male Mice in the Two-year Feed Study of Tris(chloropropyl) Phosphate

Study Day^a^ | 0 ppm | | 1,250 ppm | | | 2,500 ppm | | | 5,000 ppm
Study Day^a^ | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors
1 | 20.2 | 50 | 20.1 | 99.7 | 50 | 20.0 | 99.1 | 50 | 19.9 | 98.7 | 50
8 | 21.1 | 50 | 21.1 | 100.1 | 50 | 20.6 | 97.9 | 50 | 20.2 | 95.8 | 50
15 | 22.1 | 50 | 21.9 | 99.1 | 50 | 21.7 | 98.1 | 50 | 20.9 | 94.9 | 50
22 | 23.2 | 50 | 22.8 | 98.6 | 50 | 22.6 | 97.5 | 50 | 21.8 | 93.9 | 50
29 | 24.0 | 50 | 23.3 | 97.2 | 50 | 23.0 | 96.0 | 50 | 22.1 | 92.0 | 50
36 | 24.7 | 50 | 24.2 | 98.1 | 50 | 23.8 | 96.4 | 50 | 22.6 | 91.8 | 50
43 | 25.5 | 50 | 25.0 | 98.3 | 50 | 24.6 | 96.7 | 50 | 23.5 | 92.1 | 50
50 | 27.0 | 50 | 26.0 | 96.5 | 50 | 25.4 | 94.3 | 50 | 24.0 | 88.9 | 50
57 | 27.4 | 50 | 26.7 | 97.4 | 50 | 26.2 | 95.5 | 50 | 24.8 | 90.4 | 50
64 | 28.6 | 50 | 27.8 | 97.4 | 50 | 27.4 | 95.8 | 50 | 25.0 | 87.7 | 50
71 | 29.2 | 50 | 28.1 | 96.2 | 50 | 27.5 | 94.3 | 50 | 25.2 | 86.4 | 50
78 | 29.5 | 50 | 28.6 | 97.1 | 50 | 28.2 | 95.6 | 50 | 25.6 | 86.9 | 50
85 | 29.8 | 50 | 29.1 | 97.5 | 50 | 28.0 | 93.9 | 50 | 25.9 | 86.7 | 50
92 | 30.8 | 50 | 29.6 | 95.9 | 50 | 29.1 | 94.5 | 50 | 26.5 | 85.9 | 50
120 | 34.0 | 50 | 33.1 | 97.4 | 50 | 31.9 | 94.0 | 50 | 28.6 | 84.3 | 50
148 | 36.5 | 50 | 34.8 | 95.4 | 50 | 33.4 | 91.5 | 50 | 29.9 | 81.9 | 50
176 | 38.1 | 50 | 36.1 | 94.8 | 50 | 34.8 | 91.2 | 50 | 30.5 | 80.0 | 50
204 | 40.2 | 50 | 38.1 | 95.0 | 50 | 36.9 | 92.0 | 50 | 32.3 | 80.3 | 50
232 | 41.3 | 50 | 38.5 | 93.0 | 50 | 37.8 | 91.3 | 50 | 32.6 | 78.9 | 50
260 | 44.0 | 50 | 41.7 | 94.9 | 50 | 40.4 | 92.0 | 50 | 34.8 | 79.1 | 50
288 | 44.8 | 50 | 42.1 | 93.9 | 50 | 41.0 | 91.4 | 50 | 35.4 | 79.1 | 50
316 | 44.4 | 50 | 41.6 | 93.8 | 50 | 40.9 | 92.2 | 50 | 35.6 | 80.2 | 50
344 | 45.9 | 50 | 43.4 | 94.5 | 50 | 42.5 | 92.5 | 50 | 36.2 | 78.7 | 50
372 | 46.8 | 50 | 44.1 | 94.2 | 50 | 43.6 | 93.2 | 50 | 37.1 | 79.4 | 50
400 | 47.7 | 50 | 45.4 | 95.2 | 50 | 44.0 | 92.1 | 50 | 38.0 | 79.5 | 50
428 | 48.3 | 49 | 46.1 | 95.4 | 49 | 45.0 | 93.2 | 50 | 38.4 | 79.4 | 50
456 | 48.1 | 49 | 45.6 | 94.8 | 49 | 45.5 | 94.5 | 50 | 38.7 | 80.5 | 50
484 | 48.9 | 49 | 47.1 | 96.3 | 49 | 46.4 | 94.9 | 49 | 39.5 | 80.7 | 50
512 | 50.0 | 48 | 47.4 | 94.7 | 49 | 46.9 | 93.7 | 49 | 39.9 | 79.8 | 50
540 | 49.3 | 47 | 47.6 | 96.4 | 48 | 46.6 | 94.4 | 49 | 39.8 | 80.7 | 50
568 | 49.3 | 47 | 47.4 | 96.1 | 48 | 46.0 | 93.2 | 49 | 39.3 | 79.7 | 50
596 | 49.3 | 45 | 47.8 | 97.0 | 47 | 45.6 | 92.6 | 47 | 39.5 | 80.1 | 49
624 | 49.3 | 44 | 48.2 | 97.7 | 47 | 45.4 | 92.0 | 46 | 39.1 | 79.4 | 49
652 | 48.7 | 42 | 47.7 | 97.9 | 47 | 44.9 | 92.2 | 44 | 38.9 | 79.7 | 49
680 | 48.4 | 40 | 47.9 | 98.9 | 46 | 44.4 | 91.7 | 43 | 38.7 | 80.0 | 47
708 | 48.4 | 39 | 47.4 | 97.9 | 45 | 44.9 | 92.6 | 42 | 38.8 | 80.1 | 45
EOS | 47.6 | 38 | 46.2 | 97.0 | 44 | 43.7 | 91.8 | 42 | 39.1 | 82.1 | 43

No trend or pairwise statistical tests were performed on these data.

EOS = end of study.

^a^ Study day 1 is the day animals were placed on study.

Figure 11

Growth Curves for Male and Female Mice in the Two-year Feed Study of Tris(chloropropyl) Phosphate

Growth curves are shown for (A) males and (B) females.

Table 37 Summary of Survival and Mean Body Weights of Female Mice in the Two-year Feed Study of Tris(chloropropyl) Phosphate

Study Day^a^ | 0 ppm | | 2,500 ppm | | | 5,000 ppm | | | 10,000 ppm
Study Day^a^ | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors
1 | 17.0 | 50 | 16.9 | 99.0 | 50 | 16.8 | 98.7 | 50 | 16.8 | 98.6 | 50
8 | 17.1 | 50 | 16.8 | 97.7 | 50 | 16.6 | 96.6 | 50 | 16.3 | 95.0 | 50
15 | 18.0 | 50 | 17.7 | 98.5 | 50 | 17.4 | 96.5 | 50 | 16.9 | 94.1 | 50
22 | 19.0 | 50 | 18.8 | 98.8 | 50 | 18.4 | 96.9 | 50 | 17.7 | 93.2 | 50
29 | 19.6 | 50 | 19.0 | 97.1 | 50 | 19.0 | 97.0 | 50 | 18.0 | 92.0 | 50
36 | 20.5 | 50 | 20.4 | 99.3 | 50 | 19.7 | 96.0 | 50 | 18.6 | 90.8 | 50
43 | 21.2 | 50 | 20.9 | 98.6 | 50 | 20.2 | 95.6 | 50 | 19.1 | 90.3 | 50
50 | 22.3 | 50 | 21.6 | 96.8 | 50 | 21.0 | 94.1 | 50 | 19.9 | 89.3 | 50
57 | 22.5 | 50 | 22.0 | 97.9 | 50 | 21.5 | 95.6 | 50 | 20.2 | 89.9 | 50
64 | 23.1 | 50 | 22.9 | 99.2 | 50 | 22.0 | 95.0 | 50 | 20.8 | 89.9 | 50
71 | 24.1 | 50 | 23.4 | 97.4 | 50 | 22.5 | 93.4 | 50 | 21.3 | 88.6 | 50
78 | 24.5 | 50 | 23.8 | 97.5 | 50 | 22.9 | 93.7 | 50 | 21.5 | 88.1 | 50
85 | 24.9 | 50 | 24.8 | 99.3 | 50 | 23.4 | 93.6 | 50 | 22.0 | 88.2 | 50
92 | 25.5 | 50 | 24.4 | 95.4 | 50 | 23.3 | 91.3 | 50 | 21.7 | 85.1 | 50
120 | 28.7 | 50 | 26.7 | 92.9 | 50 | 25.2 | 87.9 | 50 | 23.2 | 80.8 | 50
148 | 30.7 | 50 | 27.4 | 89.3 | 50 | 25.9 | 84.2 | 50 | 23.8 | 77.3 | 50
176 | 33.4 | 50 | 29.5 | 88.3 | 50 | 27.8 | 83.2 | 50 | 24.7 | 74.0 | 50
204 | 35.1 | 50 | 30.8 | 87.9 | 50 | 28.7 | 81.8 | 50 | 25.2 | 71.9 | 50
232 | 34.5 | 50 | 31.9 | 92.6 | 50 | 29.7 | 86.1 | 50 | 25.9 | 75.2 | 50
260 | 38.2 | 50 | 34.3 | 89.7 | 50 | 31.7 | 82.9 | 50 | 26.7 | 69.9 | 50
288 | 38.4 | 50 | 34.5 | 89.8 | 50 | 31.9 | 82.9 | 50 | 25.6 | 66.6 | 50
316 | 39.6 | 50 | 34.5 | 87.0 | 50 | 31.5 | 79.4 | 50 | 27.0 | 68.1 | 50
344 | 40.7 | 50 | 36.5 | 89.8 | 49 | 33.7 | 82.9 | 50 | 28.0 | 68.9 | 50
372 | 42.8 | 50 | 36.5 | 85.4 | 49 | 34.6 | 80.9 | 50 | 28.1 | 65.6 | 50
400 | 44.6 | 50 | 39.2 | 88.0 | 49 | 35.1 | 78.9 | 50 | 29.2 | 65.6 | 50
428 | 46.3 | 50 | 39.6 | 85.5 | 49 | 36.0 | 77.6 | 50 | 29.8 | 64.3 | 50
456 | 46.7 | 50 | 40.1 | 86.0 | 49 | 36.0 | 77.0 | 50 | 29.9 | 63.9 | 50
484 | 49.1 | 50 | 42.6 | 86.8 | 49 | 38.2 | 77.8 | 50 | 30.9 | 62.9 | 50
512 | 48.9 | 50 | 42.0 | 85.8 | 48 | 38.0 | 77.8 | 50 | 30.6 | 62.5 | 50
540 | 50.1 | 50 | 43.7 | 87.1 | 48 | 39.3 | 78.4 | 50 | 31.6 | 63.0 | 50
568 | 50.8 | 50 | 43.3 | 85.3 | 48 | 39.3 | 77.3 | 50 | 31.9 | 62.7 | 50
596 | 50.1 | 50 | 43.4 | 86.5 | 47 | 38.4 | 76.6 | 50 | 31.5 | 62.9 | 50
624 | 50.5 | 50 | 43.9 | 86.8 | 47 | 38.9 | 76.9 | 49 | 31.5 | 62.4 | 50
652 | 51.0 | 49 | 44.1 | 86.4 | 46 | 39.3 | 77.1 | 47 | 31.9 | 62.6 | 47
680 | 51.7 | 49 | 44.3 | 85.7 | 45 | 39.5 | 76.4 | 47 | 32.4 | 62.8 | 46
708 | 51.9 | 47 | 45.0 | 86.6 | 44 | 39.3 | 75.6 | 46 | 32.2 | 62.0 | 46
EOS | 52.1 | 46 | 45.3 | 87.1 | 43 | 38.7 | 74.2 | 45 | 32.2 | 61.8 | 46

No trend or pairwise statistical tests were performed on these data.

EOS = end of study.

^a^ Study day 1 is the day animals were placed on study.

Feed consumption by all TCPP-exposed male and female mice was comparable (within 2%–6%) with that of control animals at study termination (week 102; Table 38, Table 39; Appendix H). TCPP intake, based on weekly averaging (Appendix H), was estimated to be 160, 330, and 711 mg/kg/day for male mice in the 1,250, 2,500, and 5,000 ppm groups, respectively. For female mice, TCPP intake, based on weekly averaging (Appendix H), was estimated to be 329, 673, and 1,491 mg/kg/day in the 2,500, 5,000, and 10,000 ppm groups, respectively. Table 38 and Table 39 highlight feed consumption (i.e., feed [g/day]) and estimated TCPP intake (i.e., dose [mg/kg/day]) at select time points. Similar to rats, the estimated TCPP intake was proportional to the twofold increase in TCPP concentration in dosed feed for both male and female mice. Moreover, the doses of TCPP consumed by males relative to females, in mg/kg/day, were similar for a given concentration of TCPP-exposed feed.

Table 38 Summary of Feed and Tris(chloropropyl) Phosphate Consumption of Male Mice in the Two-year Feed Study

Week | 0 ppm | 1,250 pm | | 2,500 ppm | | 5,000 ppm
Week | Feed (g/day)^a^ | Feed (g/day) | Dose (mg/kg/day)^b^ | Feed (g/day) | Dose (mg/kg/day) | Feed (g/day) | Dose (mg/kg/day)
1 | 4.6 | 4.7 | 291.8 | 5.5 | 687.2 | 5.8 | 1,454.9
13 | 4.7 | 4.7 | 201.9 | 4.8 | 428.2 | 5.4 | 1,044.0
54 | 4.6 | 4.5 | 127.5 | 4.6 | 263.7 | 4.3 | 578.8
102 | 5.4 | 5.6 | 147.6 | 5.7 | 317.7 | 5.1 | 663.1

No trend or pairwise statistical tests were performed on these data.

^a^ Grams of feed consumed/animal/day.

^b^ Milligrams of tris(chloropropyl) phosphate consumed/kilogram body weight/day.

Table 39 Summary of Feed and Tris(chloropropyl) Phosphate Consumption of Female Mice in the Two-year Feed Study

Week | 0 ppm | 2,500 ppm | | 5,000 ppm | | 10,000 ppm
Week | Feed (g/day)^a^ | Feed (g/day) | Dose (mg/kg/day)^b^ | Feed (g/day) | Dose (mg/kg/day) | Feed (g/day) | Dose (mg/kg/day)
1 | 3.3 | 4.3 | 637.6 | 4.1 | 1,219.7 | 3.4 | 2,026.2
13 | 3.7 | 3.9 | 393.5 | 4.1 | 877.9 | 4.0 | 1,817.7
54 | 4.3 | 4.3 | 294.1 | 4.1 | 592.6 | 3.9 | 1,388.9
102 | 4.7 | 4.8 | 267.0 | 4.5 | 572.9 | 4.6 | 1,428.4

No trend or pairwise statistical tests were performed on these data.

^a^ Grams of feed consumed/animal/day.

^b^ Milligrams of tris(chloropropyl) phosphate consumed/kilogram body weight/day.

#### Histopathology

This section describes the statistically significant or biologically noteworthy changes in the incidence of neoplasms and/or nonneoplastic lesions of the liver, Harderian gland, kidney, lymph node, and spleen in mice.

Liver: In male mice, there was a significant increase in the incidences of hepatocellular carcinomas in all exposed groups compared to the control group, whereas the incidences of hepatocellular adenomas remained similar across all groups including the control group (Table 40). In addition, there were slight increases in the incidence of tumor multiplicities in female mice for hepatocellular adenomas at 5,000 and 10,000 ppm, hepatocellular carcinomas at 2,500, 5,000, and 10,000 ppm, and in male mice for hepatocellular carcinomas at 1,250, 2,500, and 5,000 ppm. In male mice, there was one hepatoblastoma in the control group and one in the 5,000 ppm group. In addition, there was one hepatocholangiocarcinoma in each of the 2,500 and 5,000 ppm male groups. The incidences of nonneoplastic lesions, such as altered hepatic foci (basophilic and eosinophilic), were similar in all groups of male mice, including the control group. In female mice, there was a positive trend and significant increase at 10,000 ppm in the incidences of hepatocellular adenomas and carcinomas when compared to the control group. The incidences of nonneoplastic lesions, such as eosinophilic foci, were significantly increased in an exposure concentration-dependent manner in all exposed female mice. In addition, the 10,000 ppm group exhibited a significant increase in cytoplasmic alteration within the hepatocytes. Interestingly, this change was negligible to absent in the lower TCPP-exposed groups (Table 40).

Table 40 Incidences of Neoplastic and Nonneoplastic Lesions of the Liver in Male and Female Mice in the Two-year Feed Study of Tris(chloropropyl) Phosphate

| 0 ppm | 1,250 ppm | 2,500 ppm | 5,000 ppm
Male
n ^a^ | 50 | 50 | 50 | 50
Basophilic Focus^b^ | 4 | 4 | 3 | 2
Eosinophilic Focus | 13 | 16 | 9 | 15
Hepatocellular Adenoma (Includes Multiple)^c^
Overall rate^d^ | 21/50 (42%) | 23/50 (46%) | 18/50 (36%) | 22/50 (44%)
Adjusted rate^e^ | 44% | 47.5% | 38% | 45%
Terminal rate^f^ | 16/39 (41%) | 20/44 (46%) | 17/42 (41%) | 21/44 (48%)
First incidence (days) | 428 | 586 | 587 | 708
Poly-3 test^g^ | p = 0.506N | p = 0.444 | p = 0.350N | p = 0.542
Hepatocellular Carcinoma (Includes Multiple)^h^
Overall rate | 5/50 (10%) | 14/50 (28%) | 17/50 (34%) | 14/50 (28%)
Adjusted rate | 11% | 28.4% | 35.2% | 28.4%
Terminal rate | 3/39 (8%) | 10/44 (23%) | 14/42 (33%) | 11/44 (25%)
First incidence (days) | 653 | 413 | 469 | 666
Poly-3 test | p = 0.068 | p = 0.030 | p = 0.004 | p = 0.029
Hepatocellular Adenoma or Carcinoma (Combined)^i^
Overall rate | 23/50 (46%) | 31/50 (62%) | 31/50 (62%) | 28/50 (56%)
Adjusted rate | 48% | 62.2% | 63.6% | 56.6%
Terminal rate | 17/39 (44%) | 26/44 (59%) | 27/42 (64%) | 24/44 (55%)
First incidence (days) | 428 | 413 | 469 | 666
Poly-3 test | p = 0.319 | p = 0.112 | p = 0.087 | p = 0.257
Hepatoblastoma^j^ | 1/50 (2%) | 0/50 (0%) | 0/50 (0%) | 1/50 (2%)
Hepatocellular Adenoma, Carcinoma, or Hepatoblastoma (Combined)^k^
Overall rate | 24/50 (48%) | 31/50 (62%) | 31/50 (62%) | 29/50 (58%)
Adjusted rate | 49.8% | 62.2% | 63.6% | 58.7%
Terminal rate | 17/39 (44%) | 26/44 (59%) | 27/42 (64%) | 25/44 (57%)
First incidence (days) | 428 | 413 | 469 | 666
Poly-3 test | p = 0.291 | p = 0.150 | p = 0.119 | p = 0.249
Hepatocholangiocarcinoma^l^ | 0/50 (0%) | 0/50 (0%) | 1/50 (2%) | 1/50 (2%)
| 0 ppm | 2,500 ppm | 5,000 ppm | 10,000 ppm
Female
n | 50 | 50 | 50 | 50
Eosinophilic Focus | 1** | 7* | 13** | 16**
Hepatocyte, Cytoplasmic Alteration | 0** | 0 | 2 (1.0)^m^ | 48** (1.8)
Hepatocellular Adenoma (Includes Multiple)^n^
Overall rate | 11/50 (22%) | 5/50 (10%) | 13/50 (26%) | 23/50 (46%)
Adjusted rate | 22.2% | 10.5% | 26.5% | 47.1%
Terminal rate | 10/46 (22%) | 4/43 (9%) | 12/45 (27%) | 23/46 (50%)
First incidence (days) | 700 | 659 | 652 | 729 (T)
Poly-3 test | p < 0.001 | p = 0.100N | p = 0.400 | p = 0.007
Hepatocellular Carcinoma (Includes Multiple)^o^
Overall rate | 1/50 (2%) | 2/50 (4%) | 5/50 (10%) | 10/50 (20%)
Adjusted rate | 2% | 4.2% | 10.2% | 20.5%
Terminal rate | 0/46 (0%) | 1/43 (2%) | 5/45 (11%) | 10/46 (22%)
First incidence (days) | 716 | 689 | 729 (T) | 729 (T)
Poly-3 test | p < 0.001 | p = 0.485 | p = 0.099 | p = 0.004
Hepatocellular Adenoma or Carcinoma (Combined)^p^
Overall rate | 12/50 (24%) | 7/50 (14%) | 16/50 (32%) | 29/50 (58%)
Adjusted rate | 24.2% | 14.7% | 32.6% | 59.4%
Terminal rate | 10/46 (22%) | 5/43 (12%) | 15/45 (33%) | 29/46 (63%)
First incidence (days) | 700 | 659 | 652 | 729 (T)
Poly-3 test | p < 0.001 | p = 0.178N | p = 0.244 | p < 0.001

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05 by the Poly-3 test; **p ≤ 0.01.

(T) = terminal euthanasia.

^a^ Number of animals with tissue examined microscopically.

^b^ Number of animals with lesion.

^c^ Historical control incidence for 2-year feed studies (mean ± standard deviation): 60/149 (40.29% ± 3.74%); range: 36%–43%; all routes: 398/789 (50.04% ± 9.88%); range: 34%–70%.

^d^ Number of animals with neoplasm/number of animals necropsied.

^e^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^f^ Observed incidence at terminal euthanasia.

^g^ Beneath the control incidence is the p value associated with the trend test. Beneath the exposed group incidence is the p value corresponding to pairwise comparisons between the control group and that exposed group. The Poly-3 test accounts for differential mortality in animals that do not reach study termination. A negative trend or a lower incidence in an exposure group is indicated by N.

^h^ Historical control incidence for 2-year feed studies: 23/149 (15.44% ± 5.06%); range: 10%–20%; all routes: 201/789 (25.16% ± 9.06%); range: 10%–36%.

^i^ Historical control incidence for 2-year feed studies: 73/149 (49.02% ± 3.64%); range: 46%–53%; all routes: 513/789 (64.5% ± 10.59%); range: 46%–80%.

^j^ Historical control incidence for 2-year feed studies: 2/149 (1.35% ± 1.17%); range: 0%–2%; all routes: 25/789 (2.98% ± 2.44%); range: 0%–8%.

^k^ Historical control incidence for 2-year feed studies: 74/149 (49.69% ± 2.92%); range: 48%–53%; all routes: 520/789 (65.37% ± 10.37%); range: 48%– 80%.

^l^ Historical control incidence for 2-year feed studies: 1/149 (0.68% ± 1.18%); range: 0%–2%; all routes: 9/789 (1.14% ± 1.81%); range: 0%–6%.

^m^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

^n^ Historical control incidence for 2-year feed studies: 17/150 (11.33% ± 9.24%); range: 6%–22%; all routes: 150/839 (17.71% ± 7.01%); range: 6%– 28%.

^o^ Historical control incidence for 2-year feed studies: 3/150 (2% ± 0%); range: 2%–2%; all routes: 71/839 (8.44% ± 5.18%); range: 2%–20%.

^p^ Historical control incidence for 2-year feed studies: 20/150 (13.33% ± 9.24%); range: 8%–24%; all routes: 202/839 (23.88% ± 8.96%); range: 8%–36%.

Microscopically, hepatocellular adenomas were well-circumscribed expansile masses comprising irregular plates of hepatocyte cords with eosinophilic to basophilic cytoplasm, and occasionally vacuolated cytoplasm, with minimal to mild compression of the adjacent parenchyma. Portal triads were generally absent but occasionally were entrapped in these neoplasm masses. Hepatocellular carcinomas were large and invasive and were composed of nodules of hepatocytes arranged in solid, glandular, or trabecular patterns (Figure 12). These neoplasms in both male and female mice were also associated with increased cellular atypia accompanied by a few mitoses. Occasionally, there were areas of necrosis and hemorrhage within these masses. The hepatoblastomas are characterized by dark, basophilic masses usually accompanied by either hepatocellular adenomas or hepatocellular carcinomas. These neoplasms were composed of primitive hepatic progenitor cells, which are elongated with scant eosinophilic cytoplasm and fusiform darkly basophilic nucleoli. The hepatocholangiocarcinomas were characterized by neoplastic hepatocytes intermixed with neoplastic biliary profiles, which invade the adjacent hepatic parenchyma and can occasionally metastasize to distant organs. Hepatic foci are tinctorially discrete areas of hepatocytes that blend imperceptibly into the surrounding hepatic parenchyma with no evidence of compression or invasion (Figure 13). The cytoplasmic alterations observed in the 20,000 ppm female mice were characterized by bright eosinophilic granular cytoplasm within the hepatocytes and lack of ground glass (glycogen) cytoplasm (Figure 14). The cytoplasm of hepatocytes from control rodents with access to feed and water ad libitum are filled with glycogen and have a ground glass appearance with clear spaces (an artifact due to tissue processing) (Figure 15).

Figure 12

Representative Images of Hepatocellular Carcinoma in the Liver of a Male Mouse in the Two-year Feed Study of Tris(chloropropyl) Phosphate (H&E)

Hepatocellular carcinoma is shown in the liver of a male mouse exposed to 5,000 ppm tris(chloropropyl) phosphate in feed for 2 years. (A) The carcinoma has markedly effaced the hepatic parenchyma and the neoplastic hepatocytes are arranged as solid areas and trabeculae with multifocal areas of hemorrhage and necrosis (0.8×). (B) A higher magnification of panel A is shown (8×). The neoplastic hepatocytes are arranged in a trabecular pattern and the hepatic cord thickness varies from 2 to 10 cells thick. H&E = hematoxylin and eosin stain.

Figure 13

Representative Image of Eosinophilic Focus in the Liver of a Female Mouse in the Two-year Feed Study of Tris(chloropropyl) Phosphate (H&E)

Eosinophilic focus is shown in the liver of a female mouse exposed to 5,000 ppm tris(chloropropyl) phosphate in feed for 2 years (8.8×). These are considered nonneoplastic lesions and are composed of tinctorially (bright pink) discrete hepatocytes that blend imperceptibly into the surrounding hepatic parenchyma with no evidence of compression or invasion. H&E = hematoxylin and eosin stain.

Figure 14

Representative Image of Cytoplasmic Alteration of Hepatocytes in the Liver of a Female Mouse in the Two-year Feed Study of Tris(chloropropyl) Phosphate (H&E)

Cytoplasmic alteration of hepatocytes is shown from the liver of a female mouse exposed to 10,000 ppm tris(chloropropyl) phosphate in feed for 2 years (20×). The represented lesion indicates a mild severity and is characterized by brightly eosinophilic intracytoplasmic granules and lack the ground glass appearance of hepatocytes observed in control animals. H&E = hematoxylin and eosin stain.

Figure 15

Representative Image of Control Liver in a Female Mouse in the Two-year Feed Study of Tris(chloropropyl) Phosphate (H&E)

Normal liver is shown from a control female mouse from the tris(chloropropyl) phosphate 2-year cancer bioassay (20×). Note that the cytoplasm of the hepatocytes has a ground glass appearance and clear areas due to dissolution of glycogen during tissue processing. H&E = hematoxylin and eosin stain.

Harderian Gland: In addition to the neoplastic lesions discussed above, increases in the incidence of neoplastic lesions in the Harderian gland of male mice were observed. In male mice, there was a significant increase in the incidence of Harderian gland adenomas in the 2,500 ppm group along with higher, but nonsignificant incidences in the other exposed groups compared to the control group (Appendix H). Incidences of Harderian gland neoplasms (adenoma or carcinoma) were found in all groups of male mice, both exposed and control; however, there were no significant differences when these neoplasms were combined. There were incidences of hyperplasia within the Harderian gland in all exposed and control male groups (Appendix H). There were no increases of Harderian gland neoplasms in female mice exposed to TCPP compared to the control group (Appendix H).

Harderian gland carcinomas were characterized by neoplastic cuboidal to columnar acinar cells arranged in tubular, acinar, or solid areas, often invading the adjacent glandular epithelium. The tumor cells had varying degrees of cellular atypia and mitoses. Harderian gland adenomas were composed of neoplastic acinar epithelial cells arranged in a papillary, cystic, acinar, or combination of these morphologies and formed well demarcated nodules that compressed the surrounding glandular tissue. These neoplastic cells were usually tall and columnar with finely stippled/vacuolated eosinophilic cytoplasm and had occasional loss of nuclear polarity and atypia. Harderian gland hyperplasia was characterized by proliferative glandular epithelial cells with retained architecture of acini and did not compress or distort the adjacent glandular tissue.

In addition to the neoplasms discussed above, there were increased incidences of some nonneoplastic lesions, including cytoplasmic alteration of renal tubules in male mice, hyperplasia of lymphocytes within the mandibular lymph node in female mice, and extramedullary hematopoiesis within the spleen of female mice (Appendix H).

Kidney: There were significant increases in the incidences of cytoplasmic alteration in all exposed male mice in an exposure concentration-dependent manner (Table 41). These changes were significant by trend analysis and pairwise tests. Cytoplasmic alteration in the renal tubules of male mice was characterized by the loss of cytoplasmic vacuoles within the normal proximal renal tubules, and the resultant tubules appeared similar to that of female renal tubules, which did not have these intracytoplasmic vacuoles (Figure 16, Figure 17).

Table 41 Incidences of Nonneoplastic Lesions of the Kidney in Male Mice in the Two-year Feed Study of Tris(chloropropyl) Phosphate

| 0 ppm | 1,250 ppm | 2,500 ppm | 5,000 ppm
Kidney^a^ | 49 | 50 | 50 | 50
Renal tubule, cytoplasmic alteration^b^ | 0** | 28** (1.2)^c^ | 40** (1.2) | 48** (2.3)

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

** Statistically significant at p ≤ 0.01 by the Poly-3 test.

^a^ Number of animals examined microscopically.

^b^ Number of animals with lesion.

^c^ Average severity grade of observed lesion in affected animals: 1 = minimal; 2 = mild; 3 = moderate; 4 = marked.

Figure 16

Representative Image of Control Kidney of a Male Mouse in the Two-year Feed Study of Tris(chloropropyl) Phosphate (H&E)

A kidney section is shown from a control male mouse from the tris(chloropropyl) phosphate 2-year cancer bioassay (20×). The renal cortical tubular epithelium in male mouse kidneys usually has intracytoplasmic vacuoles. Also, note the parietal epithelium of the glomeruli is tall cuboidal in male mouse kidneys. H&E = hematoxylin and eosin stain.

Figure 17

Representative Image of Cytoplasmic Alteration in the Kidney of a Male Mouse in the Two-year Feed Study of Tris(chloropropyl) Phosphate (H&E)

Cytoplasmic alteration is shown in the kidney of a male mouse exposed to 5,000 ppm tris(chloropropyl) phosphate in feed for 2 years (20×). This lesion is diagnosed when the cytoplasmic vacuoles in the cortical tubular epithelium, which are generally seen in kidneys from control male mice, are decreased or lost. In general, these lesions are not accompanied by any apparent compromise of renal function. H&E = hematoxylin and eosin stain.

Lymph Node: For lymphocyte hyperplasia within the mandibular lymph node, there was a positive trend as well as a significantly increased incidence by pairwise test in the 10,000 ppm female mice. Lymphocyte hyperplasia was characterized by increased numbers of lymphocytes that were mature, small, and present in their respective compartments (follicular, parafollicular, or medullary cords, and intravascular); the architecture of the lymph node was generally preserved, and all the compartments were apparent within the section. These increased numbers of lymphocytes may represent an immune response. This lesion was not present in male mice (Appendix H).

Spleen: There was a significant increase in the incidence of extramedullary hematopoiesis within the spleen in the 5,000 ppm female mice. This lesion was characterized by an increase in a mixture of progenitor blood cells belonging to myeloid, erythroid, and megakaryocytic lineages. Extramedullary hematopoiesis is a normal physiological response seen in the spleen of all mice, but an increase above a certain threshold compared to the control group merits a diagnosis. In some cases, the observed increases might have been related to neoplasia or chronic toxicity, but no definitive associations could be made in this study. An increase in the incidence of this lesion was not observed in male mice (Appendix H).

## Genetic Toxicology

Data from all NTP genetic toxicity tests with TCPP are available in the NTP Chemical Effects in Biological Systems database: https://doi.org/10.22427/NTP-DATA-TR-602.^96^

### Bacterial Mutation Studies

TCPP did not induce mutations, with or without the addition of exogenous metabolic activation enzymes supplied by induced rat or hamster liver S9 in various concentrations, in any of several strains of bacteria (Salmonella typhimurium and Escherichia coli), in two bacterial mutagenicity studies (Appendix D; Table D-1, Table D-2). In the first study, the highest dose tested was limited by toxicity to 1,000 µg/plate; in the second study, although toxicity was again observed in some trials at 1,000 µg/plate, higher doses (ranging up to 6,000 µg/plate) could be tested, particularly in the E. coli strain (Appendix D).

### In Vivo Peripheral Blood Micronucleus Test

Micronuclei are biomarkers of chromosomal changes, either in chromosome number or structure (breaks). In the in vivo peripheral blood micronucleus test, TCPP exposure for 3 months via dosed feed did not result in an increase in micronucleated immature erythrocytes (polychromatic erythrocytes [PCEs]) in male or female Sprague Dawley rats (Table D-3). However, the percentage of PCEs among total erythrocytes was increased in an exposure concentration-related manner in both sexes, suggesting a stimulation of erythropoiesis in the rats exposed to TCPP. In female B6C3F1/N mice, exposure to TCPP for 3 months via dosed feed did not result in an increase in micronucleated PCEs or mature erythrocytes (normochromatic erythrocytes [NCEs]; Table D-4). In male mice, the values for micronucleated red blood cells were within the laboratory historical control 95% confidence interval and the absolute increase in micronucleated NCEs and PCEs was quite small, amounting to an increase over control values of approximately 17% or 23%, respectively. Due to the questionable biological significance of the observed increase in micronucleated cells, the results in male mice were judged to be equivocal (Table D-4). In both male and female mice, the percentage of PCEs among total erythrocytes was increased in an exposure concentration-related manner, similar to what was observed in the rat samples, suggesting that exposure to TCPP also produced a stimulation of erythropoiesis in mice.