# Materials and Methods

## Procurement and Characterization of Tris(chloropropyl) Phosphate

An isomeric mixture of tris(chloropropyl) phosphate (TCPP) was obtained from Albemarle (Orangeburg, SC) in two lots (101 and 134). Lot 101 was used in the 3-month rat and mouse studies. Lot 134 and a portion of lot 101 were blended to form lot M072911NP, which was used in the 2-year rat and mouse studies. Identity, purity, and stability analyses were conducted by the analytical chemistry laboratory at MRIGlobal (Kansas City, MO) for the study laboratory at Battelle (Columbus, OH). Reports on analyses performed in support of the TCPP studies are on file at the National Institute of Environmental Health Sciences (NIEHS).

All lots appeared as clear, colorless, oily liquids. Chemical identities of homogenized lot 101 and mixed lot M072911NP used in these studies were confirmed using proton (^1^H) and carbon-13 (^13^C) nuclear magnetic resonance (NMR) spectroscopy, infrared (IR) spectroscopy, ultraviolet-visible (UV/Vis) spectroscopy, elemental analysis, and gas chromatography (GC) with mass spectrometry (MS). Four major isomeric components were identified as tris(1-chloro-2-propyl) phosphate (isomer 1, CASRN 13674-84-5), bis(2-chloro-1-methylethyl) 2-chloropropyl phosphate (isomer 2, CASRN 76025-08-6), bis(2-chloropropyl) 2-chloroisopropyl phosphate (isomer 3, CASRN 76649-15-5), and tris(2-chloropropyl) phosphate (isomer 4, CASRN 6145-73-9) (Table 2).

Table 2 Composition of Lots Used in the Prenatal Developmental Toxicity Studies of Tris(chloropropyl) Phosphate in Rats and Mice

Analysis | Lot 101^a^ | Lot M072911NP^b^
Elemental (%)
Carbon | 33.02 | 33.01
Hydrogen | 5.64 | 5.58
Nitrogen | 0.14 | 0.10
Chlorine | 31.92 | 32.10
Water: Karl Fischer (%) | 0.0997 | 0.039
Acid Number (mg KOH/g) | 0.011 | 0.067
Ester Value (mg KOH/g) | 104.7 | 105.85
Relative Density (g/mL) | 1.2936 | 1.2959
Log P
TCPP isomer 1 | 2.69 | 2.59
TCPP isomer 2 | 2.74 | 2.65
Purity: GC/FID (%)^c^
DB-5 column
Sum of TCPP isomers | 95.94 | 97.24
Isomer 1 | 64.77 | 68.06
Isomer 2 | 26.98 | 25.43
Isomer 3 | 3.99 | 3.55
Isomer 4 | 0.20 | 0.21
Reportable Impurities % (Number)^d^ | 4.2 (10) | 2.55 (8)
DB-WAX column
Sum of TCPP isomers | ND | 97.71
Isomer 1 | ND | 68.35
Isomer 2 | ND | 25.65
Isomer 3 | ND | 3.54
Isomer 4 | ND | 0.18
Reportable Impurities % (Number)^d^ | ND | 2.29 (6)

KOH = potassium hydroxide; TCPP = tris(chloropropyl) phosphate; GC/FID = gas chromatography/flame ionization detection; ND = not determined.

^a^ Lot 101 was used in the 3-month studies, however, elemental analysis, relative density, and log P measurements were made after the 3-month studies and before the 2-year studies.

^b^ Lots 101 and 134 were blended to generate lot M072911NP used in the 2-year studies; all values except acid number, ester value, and log P are averages between two different drums of the test article.

^c^ Isomers 1 through 4 were identified as tris(1-chloro-2-propyl) phosphate, bis(2-chloro-1-methylethyl) 2-chloropropyl phosphate, bis(2 chloropropyl) 2-chloroisopropyl phosphate, and tris(2-chloropropyl) phosphate, respectively (Appendix A).

^d^ Impurities ≥0.05% are listed.

Multiple physical properties were also measured to characterize TCPP: acid number and ester value, octanol/water partition coefficients (log P) of isomers 1 and 2, density, and an extinction coefficient, Є_max_, at 280 nm. Moisture content of lots 101 and M072911NP was determined by Karl Fischer titration, and the purity profiles were measured using gas chromatography (GC) with flame ionization detection (FID). Accelerated stability studies were conducted using GC/FID, and the stability of the bulk chemical was confirmed for at least 2 weeks when stored at temperatures up to 60°C. The purities of lots 101 and M072911NP were reevaluated before, during, and after the studies; all purity reanalyses determined the test articles as statistically similar to a frozen reference sample of the same lots. Purity results are described in Appendix A.

## Preparation and Analysis of Dose Formulations

Dose formulations were prepared approximately monthly by mixing TCPP with NIH-07 or NTP-2000 feed (Appendix A). The rat studies used dose formulations of 0, 2,500, 5,000, 10,000, and 20,000 ppm, whereas the mouse studies used dose formulations of 0, 1,250, 2,500, 5,000, 10,000, and 20,000 ppm. The 3-month rat study included an additional formulation at 40,000 ppm.

Before the 3-month studies, the study laboratory conducted homogeneity studies of the 2,500 and 40,000 ppm dose formulations in 25 kg NIH-07 batch sizes and the 1,250 and 40,000 ppm dose formulations in 25 kg NTP-2000 batch sizes using GC/FID. Additional homogeneity studies of the 2,500 and 20,000 ppm dose formulations in 65 kg NIH-07 batch sizes and the 1,250 and 20,000 ppm dose formulations in 84 kg NTP-2000 batch sizes were performed before the 2-year studies by the study laboratory using GC/FID. All formulations were determined to be homogenous and of appropriate concentration.

Stability studies of TCPP in NIH-07 and NTP-2000 feed prepared at 3,000 ppm were performed by the analytical laboratory MRIGlobal (Kansas City, MO) using GC/FID. It was concluded that TCPP formulations could be stored up to 42 days frozen with ≤4.4% loss of TCPP. Dose formulations for the 3-month and 2-year studies were stored frozen (−15ºC to −30ºC) in sealed containers protected from light and were used within 42 days after preparation.

Periodic analyses of the dose formulations of TCPP were conducted by the study laboratory to determine purity (Table A-4, Table A-5, Table A-6, Table A-7). All preadministration dose formulations were within 10% of target concentrations. In the 3-month rat study, all samples were within 10% of the target concentrations except for four samples of collected residual feed from the feeders (−10.1% to −17.3%). In the 3-month mouse study, all samples were within 10% of the target concentrations except for three samples collected from the feeders and one sample from the storage bucket (−10.9% to −14.9%). In the 2-year rat study, all samples were within 10% of the target concentrations except for two samples from the storage barrel (−16.0% and −10.3%). All samples in the 2-year mouse study were within 10% of the target concentrations.

## Animal Source

Time-mated (F_0_) female Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) rats were obtained from Envigo (formerly Harlan Laboratories, Inc., Indianapolis, IN). Male and female B6C3F1/N mice were obtained from the National Toxicology Program (NTP) colony maintained by Taconic Biosciences, Inc. (Germantown, NY).

## Animal Welfare

Animal care and use are in accordance with the Public Health Service Policy on Humane Care and Use of Animals. All animal studies were conducted in an animal facility accredited by AAALAC International. Studies were approved by the Battelle (Columbus, OH) Animal Care and Use Committee and conducted in accordance with all relevant National Institutes of Health (NIH) and NTP animal care and use policies and applicable federal, state, and local regulations and guidelines.

## Three-month Studies

### Exposure Concentration Selection Rationale

Exposure concentrations for the 3-month studies were selected based on palatability studies in adult Wistar Han rats and B6C3F1 mice (data not shown). Male and female rats and mice were provided NTP-2000 rodent diet containing TCPP at target concentrations of 0, 30,000, 40,000, or 50,000 ppm for a maximum of 14 consecutive days (n = 5/sex). In rats, 40,000 ppm was considered the maximum tolerated dose; at this exposure concentration, one female was euthanized, and one male died. Animals in this exposure group also had body weight reductions accompanied by lower feed consumption. Clinical signs—such as dehydration, thinness, rough hair coat, discolored urine, and hyperactivity—were dependent on exposure concentration. Mice were more sensitive than rats to TCPP in the palatability studies. At the lowest exposure concentration of 30,000 ppm, male and female mice experienced clinical signs of toxicity including thinness, dehydration, and rough hair coat throughout the 14-day exposure period. Higher concentrations were not well tolerated, and mice exhibited lower mean body weight and feed consumption. These data informed the decision to provide TCPP to rats in feed at concentrations of 0, 2,500, 5,000, 10,000, 20,000, or 40,000 ppm and to mice at concentrations of 0, 1,250, 2,500, 5,000, 10,000, or 20,000 ppm.

### Study Design for Rats

F_0_ female Sprague Dawley rats were 11 to 12 weeks old upon receipt. Evidence of mating is defined as gestation day (GD) 1; F_0_ females were received on GD 2 and held for 4 days. They were randomly assigned to one of six exposure groups on GD 5. Randomization was stratified by body weight that produced similar group mean body weights using PATH/TOX SYSTEM software (Xybion Medical Systems Corporation, Lawrenceville, NJ).

F_0_ females were quarantined for 39 days after receipt. Ten nonmated females received with the time-mated females were designated for disease monitoring 2 days after arrival; samples were collected for serological analyses, and the rats were euthanized, necropsied, and examined for the presence of disease or parasites. The health of the F_1_ animals was monitored during the study according to the protocols of the NTP Sentinel Animal Program (Appendix C). All test results were negative.

Beginning on GD 6, groups of 20 (0, 2,500, 10,000, and 40,000 ppm) or 8 (5,000 and 20,000 ppm) F_0_ time-mated females were fed diets containing 0, 2,500, 5,000, 10,000, 20,000, or 40,000 ppm TCPP throughout gestation and lactation. Groups of 10 F_1_ rats/sex/exposure concentration continued on study after weaning and were fed diets containing the same respective TCPP concentrations for 3 months.

F_0_ female rats were housed individually during gestation and with their respective litters during lactation. Water and dosed feed were available ad libitum. F_0_ females were weighed on GDs 5, 6, 9, 12, 15, 18, and 21 and on lactation days (LDs) 1, 4, 7, 14, and 21. During gestation, feed consumption was continuously measured over 3-day intervals from GD 6 through GD 21 (GDs 6–9, 9–12, 12–15, 15–18, and 18–21). The day of parturition was considered to be postnatal day (PND) 0. On apparent GD 27, all time-mated females that failed to deliver were euthanized and the uteri were examined and stained for evidence of implantation. Total litter weight and litter weight by sex were collected on PND 1. Individual F_1_ pups were weighed on PNDs 4, 7, 14, and 21. Clinical observations and survival were evaluated throughout lactation. During lactation, feed consumption was continuously measured over 3-day intervals from LD 1 through LD 21 (LDs 1–4, 4–7, 7–10, 10–14, 14–17, and 17–21).

Select dams and their litters were removed on GD 18 and LD 4 to quantify TCPP plasma and tissue concentrations in the 0, 2,500, and 10,000 ppm groups. On GD 18, blood was collected from the retroorbital site of randomly selected dams (n = 5/exposure group). Blood samples were collected in tubes containing ethylenediaminetetraacetic acid (EDTA) and centrifuged, and the plasma was harvested. Amniotic fluid was collected and pooled by litter. Dams’ fetuses were collected, pooled by litter, and flash frozen in liquid nitrogen. On LD 4, randomly selected dams (n = 5/exposure group) from the 0, 2,500 and 10,000 ppm groups were selected for biological sampling. Plasma was collected in the same manner as on GD 18. Up to two randomly selected pups were collected on PND 4 from each dam and flash frozen in liquid nitrogen. All samples were stored frozen at approximately −20°C before shipment to MRIGlobal (Kansas City, MO) for analysis.

F_1_ litters were standardized on PND 4 to eight pups per litter, with at least two pups of each sex and a preference for four males and four females each. Litters that did not meet the minimum of eight pups (or if they had fewer than two pups of either sex) were removed from the study. On the day the last litter reached PND 19, pups were randomly assigned to the 3-month study. For all exposure concentrations, two pups per sex from five randomly selected litters per exposure group were chosen for the 3-month study. After assignments to the 3-month study were complete, five pups per sex from the remaining vehicle control pups were randomly selected as the study termination sentinel animals. On the day the last litter reached PND 21, dams were removed, and the pups were weaned. Weaning marked the beginning of the 3-month study.

After weaning, F_1_ rats were housed five per cage. Water and dosed feed were available ad libitum. Feed consumption was measured weekly for 3 months. Cages were changed weekly though PND 4, then changed twice weekly. Racks were changed and rotated at least every 2 weeks. Further details of animal maintenance are given in Table 3.

Table 3 Experimental Design and Materials and Methods in the Three-month and Two-year Feed Studies of Tris(chloropropyl) Phosphate

Three-month Studies | Two-year Studies
Study Laboratory
Battelle (Columbus, OH) | Same as 3-month studies
Strain and Species
Rats: Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) | Same as 3-month studies
Mice: B6C3F1/N
Animal Source
Rats: Envigo (formerly Harlan Laboratories, Inc., Indianapolis, IN) | Same as 3-month studies
Mice: Taconic Biosciences, Inc. (Germantown, NY)
Time Held Before Studies
F_0_ female rats: 4 days | F_0_ female rats: Same as 3-month study
Mice: 15 (females) or 16 (males) days | Mice: 11 (females) or 12 (males) days
Average Age When Studies Began
F_0_ female rats: 11–12 weeks | F_0_ female rats: 11–15 weeks
Mice: 6–7 weeks | Mice: 5–6 (females) or 6 (males) weeks
Date of First Exposure
F_0_ female rats: August 7, 2009 | F_0_ female rats: October 28, 2011
F_1_ rats: September 13 (males) or 14 (females), 2009 | F_1_ rats: December 12 (males) or 13 (females), 2011
Mice: September 10 (females) or 11 (males), 2009 | Mice: October 24 (females) or 25 (males), 2011
Duration of Exposure
F_0_ female rats: GD 6 through LD 21 | F_0_ female rats: GD 6 through LD 28
F_1_ rats: Perinatal plus 3 months | F_1_ rats: Perinatal plus 2 years
Mice: 3 months | Mice: 2 years
Date of Last Exposure
F_0_ female rats: September 13, 2009 | F_0_ female rats: December 12, 2011
F_1_ rats: December 16 (males) or 17 (females), 2009 | F_1_ rats: December 12 (males) or 17 (females), 2013
Mice: December 14 (females) or 15 (males), 2009 | Mice: October 24 (females) or 29 (males), 2013
Necropsy Dates
F_1_ rats: December 16 (males) or 17 (females), 2009 | F_1_ rats: December 9–12 (males) or 12–17 (females), 2013
Mice: December 14 (females) or 15 (males), 2009 | Mice: October 21–24 (females) or 24–25, 28–29 (males), 2013
Average Age at Necropsy
F_1_ rats: 17 weeks | F_1_ rats: 109 (males) or 109–110 (females) weeks
Mice: 19–20 (females) or 20 (males) weeks | Mice: 109–111 (females) or 110–111 (males) weeks
Size of Study Groups
F_0_ female rats: 20 (0, 2,500, 10,000, 40,000 ppm) or 8 (5,000, 20,000 ppm) | F_0_ female rats: 38
F_1_ rats: 10/sex (0, 2,500, 5,000, 10,000, 20,000 ppm) | F_1_ rats (2-year study): 50/sex F_1_ rats (internal dosimetry): 10/sex
Mice: 10/sex | Mice (2-year study): 50/sex Mice (internal dosimetry): 20/sex
Method of Distribution
Animals were distributed randomly into groups of approximately equal initial mean body weights | Same as 3-month studies
Animals/Cage
F_0_ female rats: 1 (with litter) | F_0_ female rats: 1 (with litter)
F_1_ rats: 5 (males) or 5 (females) | F_1_ rats: 2 (males) or up to 4 (females)
Mice: 1 (males) or up to 5 (females) | Mice: 1 (males) or up to 4 (females)
Method of Animal Identification
F_0_ female rats: Cage card and tail marking with permanent pen | Rats: Same as 3-month studies
F_1_ rats (pups): Limb tattoo
F_1_ rats (3-month): Cage card and tail tattoo
Mice: Tail tattoo | Mice: Cage card and tail tattoo
Diet
Rats: Irradiated NIH-07 meal feed (perinatal phase) or irradiated NTP-2000 meal feed (postweaning) (Zeigler Brothers, Inc., Gardners, PA), available ad libitum either untreated or supplemented with TCPP, changed twice weekly | Rats: Same as 3-month studies
Mice: Irradiated NTP-2000 meal feed (Zeigler Brothers, Inc., Gardners, PA), available ad libitum either untreated or supplemented with TCPP, changed twice weekly | Mice: Same as 3-month studies
Water
Tap water (Columbus municipal supply) via automatic watering system (Edstrom Industries, Inc., Waterford, WI), available ad libitum | Same as 3-month studies
Cages
Rats: Solid polycarbonate (Lab Products, Inc., Seaford, DE), changed weekly (dams and litters through PND 4) or twice weekly (group housed rats), rotated every 2 weeks following the perinatal phase | Same as 3-month studies
Mice: Solid polycarbonate (Lab Products, Inc., Seaford, DE), changed weekly (males) or twice weekly (females), rotated every 2 weeks | Same as 3-month studies
Bedding
Irradiated Sani-Chips^®^ (P.J. Murphy Forest Products Corporation, Montville, NJ), changed with cage changes | Same as 3-month studies
Rack Filters
Spun-bonded polyester (Snow Filtration Company, Cincinnati, OH), changed every 2 weeks | Same as 3-month studies
Racks
Stainless steel (Lab Products, Inc., Seaford, DE), changed and rotated every 2 weeks | Same as 3-month studies
Animal Room Environment
Temperature: 72°F ± 3°F Relative humidity: 50% ± 15% Room fluorescent light: 12 hours/day Room air changes: at least 10/hour | Same as 3-month studies
Exposure Concentrations
Rats: 0, 2,500, 5,000, 10,000, 20,000, or 40,000 (F_0_ females only) ppm in feed | Rats: 0, 2,500, 5,000, 10,000, or 20,000 ppm in feed
Mice: 0, 1,250, 2,500, 5,000, 10,000, or 20,000 ppm in feed | Mice: 0, 1,250 (males only), 2,500, 5,000, or 10,000 (females only) ppm in feed
Type and Frequency of Observation
F_0_ female rats: Observed twice daily. Weighed on GDs 5, 6, 9, 12, 15, 18, and 21 and on LDs 1, 4, 7, 14, and 21. Feed consumption was measured continuously from GD 6 through LD 21. Parturition checks recorded from GD 21 through GD 25. | F_0_ female rats: Observed twice daily. Weighed on arrival, on GDs 5, 6, 9, 12, 15, 18, and 21 and on LDs 1, 4, 7, 10, 14, 17, 21, 24, and 28. Feed consumption was measured on GDs 6, 9, 12, 15, 18, and 21 and on LDs 1, 4, 7, 10, 14, 17, 21, 24, and 28. Parturition checks recorded from GD 21 through GD 25.
F_1_ rats: Observed twice daily. Litter data (litter count by sex, litter weights by sex, and litter observations) were recorded on PND 1. Daily litter counts were performed throughout the lactation period. Pups were weighed on PNDs 4, 7, 14, and 21, on study day 1, weekly thereafter, and at study termination. Clinical observations were recorded on study day 1, weekly thereafter, and at study termination. Feed consumption was recorded weekly. | F_1_ rats: Observed twice daily. Litter data (litter count by sex, litter weights by sex, and litter observations) were recorded on PND 1. Pups/litter were recorded on PNDs 2 and 3. Pups were weighed on PNDs 4, 7, 10, 14, 17, 21, 24, and 28, on study day 1, weekly for the first 13 weeks, every 4 weeks thereafter, and at study termination. Clinical observations were recorded every 4 weeks and at study termination. Feed consumption was recorded weekly for the first 13 weeks, every 4 weeks thereafter, and at study termination.
Mice: Observed twice daily. Weighed initially, weekly thereafter, and at study termination. Clinical observations were recorded on study day 1, weekly thereafter, and at study termination. Feed consumption was recorded weekly. | Mice: Observed twice daily. Weighed initially, weekly for the first 13 weeks, every 4 weeks thereafter, and at study termination. Clinical observations were recorded every 4 weeks and at study termination. Feed consumption was recorded weekly for 13 weeks, every 4 weeks thereafter, and at study termination.
Method of Euthanasia
Carbon dioxide | Same as 3-month studies
Necropsy
Necropsies were performed on all F_1_ rats and all mice. Organs weighed at study termination were: liver, thymus, right kidney, right testis, heart, and lungs. | Necropsies were performed on all F_1_ rats and all mice.
Clinical Pathology
At study termination, blood was collected from the retroorbital site for hematology, clinical chemistry (F_1_ rats only), and erythrocyte micronuclei determinations. | None
Hematology: erythrocyte count, mean cell volume, hemoglobin, hematocrit, mean cell hemoglobin, mean cell hemoglobin concentration, white blood cell count and differential, reticulocyte count, and platelet count. Additionally, a qualitative evaluation of morphological features in red blood cells and platelets and a manual hematocrit were performed.
Clinical Chemistry (F_1_ rats only): alanine aminotransferase, sorbitol dehydrogenase, alkaline phosphatase, total bile acids, creatinine, urea nitrogen, glucose, albumin, total protein, creatine kinase, cholesterol, and triglycerides.
Histopathology
F_1_ rats: Complete histopathology was performed on all 0 and 20,000 ppm male and female rats, all 10,000 ppm male rats, and those with gross lesions. In addition to gross lesions and tissue masses, the following tissues were examined: adrenal glands, brain (frontal cortex and basal ganglia, parietal cortex and thalamus, and cerebellum and pons), clitoral glands, esophagus, eyes, femur (including diaphysis with marrow cavity and epiphysis [femoral condyle with epiphyseal cartilage plate, articular cartilage and articular surface]), Harderian gland, heart and aorta, large intestine (cecum, colon, and rectum), small intestine (duodenum, jejunum, and ileum), kidneys, liver (two sections including left lateral lobe and median lobe), lungs and mainstem bronchi, lymph nodes (mandibular and mesenteric), mammary gland and adjacent (inguinal) skin, nasal cavity with turbinates (three sections), ovaries, pancreas, parathyroid glands, pituitary gland, preputial glands, prostate, salivary glands, seminal vesicles, spleen, stomach (forestomach and glandular), testis with epididymides, thymus, thyroid gland, trachea, urinary bladder, and uterus. Liver and mandibular lymph nodes were also examined in the female 10,000 ppm rats. The liver, bone marrow, thymus, spleen, and lymph nodes were identified as target organs and examined to a no-effect level. | F_1_ rats: Complete histopathology was performed on all rats. In addition to gross lesions and tissue masses, the following tissues were examined: adrenal glands, brain (olfactory bulbs, frontoparietal cortex and basal ganglia, mid-parietal cortex and thalamus, mid-brain with substantia nigra and red nucleus, posterior colliculi, mid-cerebellum including cranial nerve VIII, and posterior medulla), clitoral glands, esophagus, eyes, femur (including diaphysis with marrow cavity and epiphysis [femoral condyle with epiphyseal cartilage plate, articular cartilage and articular surface]), Harderian gland, heart and aorta, large intestine (cecum, colon, and rectum), small intestine (duodenum, jejunum, and ileum), kidneys, liver (two sections including left lateral lobe and median lobe), lungs and mainstem bronchi, lymph nodes (mandibular and mesenteric), mammary gland with adjacent (inguinal) skin, nasal cavity and nasal turbinates (three sections), ovaries, pancreas, parathyroid glands, pituitary gland, preputial glands, prostate, salivary glands, seminal vesicles, spleen, stomach (forestomach and glandular), testis with epididymides, thymus, thyroid gland, trachea, urinary bladder, uterus, and vagina with cervix. If neurological signs were present, the spinal cord and nerves (sciatic, tibial, and trigeminal with ganglion) were examined. If neuromuscular signs were present, the thigh muscle was examined.
Mice: Complete histopathology was performed on all 0 and 20,000 ppm mice. In addition to gross lesions and tissue masses, the following tissues were examined: adrenal glands, brain (frontal cortex and basal ganglia, parietal cortex and thalamus, and cerebellum and pons), clitoral glands, esophagus, eyes, femur (including diaphysis with marrow cavity and epiphysis [femoral condyle with epiphyseal cartilage plate, articular cartilage and articular surface]), gallbladder, Harderian gland, heart and aorta, large intestine (cecum, colon, and rectum), small intestine (duodenum, jejunum, and ileum), kidneys, liver (two sections including left lateral lobe and median lobe), lungs and mainstem bronchi, lymph nodes (mandibular and mesenteric), mammary gland and adjacent (inguinal) skin, nasal cavity with turbinates (three sections), ovaries, pancreas, parathyroid glands, pituitary gland, preputial glands, prostate, salivary glands, seminal vesicles, spleen, stomach (forestomach and glandular), testis with epididymides, thymus, thyroid gland, trachea, urinary bladder, and uterus. The liver and kidney were identified as target organs and examined to a no-effect level. | Mice: Complete histopathology was performed on all mice. In addition to gross lesions and tissue masses, the following tissues were examined: adrenal glands, brain (olfactory bulbs, frontoparietal cortex and basal ganglia, mid-parietal cortex and thalamus, mid-brain with substantia nigra and red nucleus, posterior colliculi, mid-cerebellum including cranial nerve VIII, and posterior medulla), clitoral glands, esophagus, eyes, femur (including diaphysis with marrow cavity and epiphysis [femoral condyle with epiphyseal cartilage plate, articular cartilage and articular surface]), gallbladder, Harderian gland, heart and aorta, large intestine (cecum, colon, and rectum), small intestine (duodenum, jejunum, and ileum), kidneys, liver (two sections including left lateral lobe and median lobe), lungs and mainstem bronchi, lymph nodes (mandibular and mesenteric), mammary gland with adjacent (inguinal) skin, nasal cavity and nasal turbinates (three sections), ovaries, pancreas, parathyroid glands, pituitary gland, preputial glands, prostate, salivary glands, seminal vesicles, spleen, stomach (forestomach and glandular), testis with epididymides, thymus, thyroid gland, trachea, urinary bladder, and uterus.
Thymus Morphometry
F_1_ rats: Morphometric analysis was performed on thymus sections from all rats. The total thymus, medulla (light), and cortex (dark) areas (mm^2^) were quantified. | None
Molecular Pathology
None | Male mice: Hepatocellular carcinomas arising spontaneously or following chronic TCPP exposure were subjected to whole-exome sequencing, RNA-seq, and miRNA-seq. Tissues were flash frozen during necropsy and stored at −80°C until DNA and RNA were extracted for appropriate library preparation and subsequent next-generation sequencing studies. Additional details are available in Appendix G.
Sperm Motility and Vaginal Cytology
At study termination, sperm samples were collected from F_1_ male rats in the 0, 2,500, 5,000, and 10,000 ppm groups and from male mice in the 0, 5,000, 10,000, and 20,000 ppm groups for sperm count and motility evaluations. The following parameters were evaluated: epididymal spermatozoal motility and concentration. The left cauda, left epididymis, and left testis were weighed. Vaginal samples were collected for up to 16 consecutive days before study termination from F_1_ female rats in the 0, 5,000, 10,000, and 20,000 ppm groups and from female mice in the 0, 5,000, 10,000, and 20,000 ppm groups for vaginal cytology evaluations. Due to the poor quality of samples, an assessment of estrous cyclicity could not be made for female rats. Estrous cyclicity was evaluated in female mice; however, missing values in the data set precluded conclusive interpretations regarding effects of the administered TCPP. | None
Internal Dose Assessment
Rats: Maternal plasma (n = 5), amniotic fluid (pooled by litter), and fetal (pooled by litter) TCPP concentrations were measured at GD 18; maternal plasma (n = 5) and whole pup concentrations were measured at LD 4 from the 0, 2,500, and 10,000 ppm groups. The samples were not collected following a protocol to stabilize the parent in matrix or to minimize the background contamination, which led to highly variable results; hence, these data are not reported here. | Rats: Maternal (n = 5) and pup (n = 5/sex) plasma TCIPP concentrations were measured at LD 28 using a validated analytical method and results are published by Collins et al.^56^ Concentrations were also measured in F_1_ male and female rats (n = 10/sex) at 3, 6, 12, and 18 months.
Mice: None | Mice: Plasma (n = 5/sex) TCIPP concentrations were measured at 3, 6, 12, and 18 months using a validated analytical method and results are published by Collins et al.^56^

GD = gestation day; LD = lactation day; PND = postnatal day; TCPP = tris(chloropropyl) phosphate; TCIPP = tris(1-chloro-2-propyl) phosphate.

Two diets were used in the rat studies: (1) NIH-07 during the perinatal phase and (2) NTP-2000 during the postnatal phase. The NIH-07 diet is a higher protein diet that supports reproduction and lactation in rodents, whereas the NTP-2000 diet is a lower protein diet that decreases the incidence of chronic nephropathy in adult rats. Information on feed composition and contaminants for both diets is provided in Appendix B.

### Study Design for Mice

Male and female B6C3F1/N mice were 4 to 5 weeks old upon receipt and were quarantined for 15 (females) or 16 (males) days before study start. Mice were randomly assigned to one of six exposure groups (n = 10 mice/sex/group). Randomization was stratified by body weight that produced similar group mean weights using PATH/TOX SYSTEM software (Xybion Medical Systems Corporation, Lawrenceville, NJ). Mice were fed diets containing 0, 1,250, 2,500, 5,000, 10,000, or 20,000 ppm TCPP for 3 months.

Five male and five female mice were randomly selected for parasite evaluation and gross observation of disease. The health of the mice was monitored during the study according to the protocols of the NTP Sentinel Animal Program (Appendix C). All test results were negative.

Mice were housed individually (males) or up to five (females) per cage. Water and dosed feed were available ad libitum. Feed consumption was measured weekly for 3 months. Cages were changed at least once weekly (males) or twice weekly (females) and rotated every 2 weeks. Racks were changed and rotated every 2 weeks. Further details of animal maintenance are given in Table 3. Information on feed composition and contaminants is given in Appendix B.

### Clinical Examinations and Pathology

In the 3-month studies in rats and mice, animals were observed twice daily for signs of morbidity and moribundity and were weighed before dosed feed exposure on study day 1, weekly for 3 months, and at study termination. Clinical observations were recorded on study day 1, weekly for 3 months, and at study termination. Feed consumption was determined weekly throughout the studies.

Blood was collected from the retroorbital plexus (rats) or sinus (mice) at the end of the 3-month studies for hematology, clinical chemistry (rats only), and micronuclei determination. Animals were anesthetized with a carbon dioxide/oxygen mixture and bled in a random order. Blood was collected in tubes containing EDTA (for hematology and micronuclei determination) or serum separator tubes (for clinical chemistry). Hematology parameters were analyzed using an Advia^®^ 120 system (Bayer Diagnostics Division, Tarrytown, NY). Clinical chemistry parameters were analyzed using the Roche cobas^®^ c501 Chemistry Analyzer (Roche Diagnostics, Indianapolis, IN). The parameters measured are listed in Table 3. Samples for erythrocyte micronuclei determination were stored at 2°C–8°C immediately after collection and shipped that day to Integrated Laboratory Systems, LLC (ILS, Durham, NC) for analysis.

At the end of the 3-month studies, samples were collected for sperm motility and vaginal cytology evaluations from F_1_ male and female rats in the 0, 2,500 (males only), 5,000, 10,000, and 20,000 (females only) ppm groups and male and female mice in the 0, 5,000, 10,000, and 20,000 ppm groups. The parameters evaluated are listed in Table 3. Due to low cellularity and poor quality of samples, estrous cyclicity could not be determined for female rats. Estrous cyclicity was evaluated in female mice; however, missing values in the data set precluded conclusive interpretations regarding effects of the administered TCPP. Male animals were evaluated for sperm count and motility. The left testis and left epididymis were isolated and weighed. The tail of the epididymis (cauda epididymis) was then removed from the epididymal body (corpus epididymis) and weighed. Test yolk (rats) or modified Tyrode’s buffer (mice) was applied to slides, and a small incision was made at the distal border of the cauda epididymis. The sperm that effluxed from the incision were dispersed in the buffer on the slides, and the numbers of motile and nonmotile spermatozoa were counted for five fields per slide by two observers. After completion of sperm motility estimates, each left cauda epididymis was placed in buffered saline solution. Caudae were finely minced, and the tissue was incubated in the saline solution and then heat fixed at 65°C. Sperm density was determined microscopically with the aid of a hemocytometer. To quantify spermatogenesis, the testicular spermatid head count was determined by removing the tunica albuginea and homogenizing the left testis in phosphate-buffered saline containing 10% dimethyl sulfoxide. Homogenization-resistant spermatid nuclei were counted with a hemocytometer.

Necropsies were performed on all rats and mice at the end of the 3-month studies. Organ weights were recorded for the liver, thymus, right kidney, right testis, heart, and lungs. At necropsy, all organs and tissues were examined for grossly visible lesions and all major tissues were fixed and preserved in 10% neutral buffered formalin except for eyes, which were first fixed in Davidson’s solution, and testes, vaginal tunics, and epididymides, which were first fixed in modified Davidson’s solution. Tissues were processed and trimmed, embedded in paraffin, sectioned at a thickness of approximately 5 μm, and stained with hematoxylin and eosin (H&E) for microscopic examination. Complete histopathological examinations were performed by the study laboratory pathologist on all organs with gross lesions and on all tissues collected from the 0 and 20,000 ppm rats and mice. Due to overt toxicity of TCPP in the male rats at 20,000 ppm, all protocol-required tissues were examined in the 10,000 ppm group, as well. In rats, the liver, bone marrow, thymus, spleen, and lymph nodes were identified as target organs and examined to a no-effect level. In mice, the liver and kidney were identified as target organs and examined to a no-effect level. Tissues examined microscopically are listed in Table 3.

Morphometric analysis was performed on H&E-stained rat thymus sections from all exposure groups to better characterize the increase in thymus weights within male and female rats exposed to TCPP. Slides were scanned at 40× using the Aperio^®^ Scanscope XT^®^ Digital Slide Scanner (Leica Biosystems, Buffalo Grove, IL) and viewed using ImageScope^®^ software (v. 10.2.0.2352, Leica Biosystems). Image analysis was performed on the entire thymus section using the Definiens Tissue Studio^®^ software (v. 3.6.1, Carlsbad, CA). Specific regions of interest were selected across multiple thymic samples using the Composer^®^ algorithm, training the algorithm to identify the cortical (dark) and medullary (light) regions. The algorithm was then applied across all prepared thymic tissue sections to quantitate the percentage of dark and light staining areas. The total thymic area was quantified for each sample for relative comparison of the cortical and medullary areas.

After a review of the laboratory reports and selected histopathology slides by a quality assessment (QA) pathologist, the findings and reviewed slides were submitted to a Pathology Peer Review Group (PPR) coordinator for a second independent review. Any inconsistencies in the diagnoses made by the study laboratory and QA pathologists were resolved by the pathology peer-review process. Final diagnoses for reviewed lesions represent a consensus of the PPR or a consensus between the study laboratory pathologists, Division of Translational Toxicology (DTT) pathologist, QA pathologist, and the PPR coordinator. Details of these review procedures have been described, in part, by Maronpot and Boorman^53^ and Boorman et al.^54^

## Two-year Studies

### Study Design for Rats

F_0_ female Sprague Dawley rats were 11 to 15 weeks old upon receipt. Evidence of mating is defined as GD 1; F_0_ females were received on GD 2 and held for 4 days. F_0_ females were randomly assigned to one of five exposure groups on GD 5. Randomization was stratified by body weight that produced similar group mean weights using PATH/TOX SYSTEM software (Xybion Medical Systems Corporation, Lawrenceville, NJ).

F_0_ females were quarantined for 11 days after receipt. Ten nonmated females received with the time-mated females were designated for disease monitoring 4 days after arrival; samples were collected for serological analyses, and the rats were euthanized, necropsied, and examined for the presence of disease or parasites. The health of the F_1_ rats was monitored during the study according to the protocols of the NTP Sentinel Animal Program (Appendix C). Pinworms (Syphacia spp.) were diagnosed in sentinel animals during routine health monitoring evaluations. Infected animals did not display clinical signs, and no pathological lesions were noted in relation to the presence of the pinworms. Following this finding, DTT, in coordination with the testing laboratory, developed and implemented a successful plan of pinworm containment and eradication, without the use of medication. The NTP Sentinel Animal Program required the testing laboratories to actively monitor animals to ensure the continued exclusion of pinworms from all studies going forward. All other test results were negative.

Beginning on GD 6, groups of 38 F_0_ time-mated female rats were fed diets containing 0, 2,500, 5,000, 10,000, or 20,000 ppm TCPP throughout gestation and lactation. Groups of 50 F_1_ rats/sex/exposure concentration continued on study after weaning and were fed diets containing the same respective TCPP concentrations for 2 years.

F_0_ female rats were housed individually during gestation and with their respective litters during lactation. Water and dosed feed were available ad libitum. F_0_ female body weights were recorded on GDs 5, 6, 9, 12, 15, 18, and 21 and on LDs 1, 4, 7, 10, 14, 17, 21, 24, and 28. During gestation, feed consumption was continuously measured over 3-day intervals from GD 6 through GD 21 (GDs 6–9, 9–12, 12–15, 15–18, and 18–21). The day of parturition was considered to be LD 0. On apparent GD 25, all time-mated female rats that failed to deliver were euthanized and the uteri were examined and stained for evidence of implantation. Total litter weight and litter weights by sex were collected on PND 1. Individual F_1_ pup weights were recorded on PNDs 4, 7, 10, 14, 17, 21, 24, and 28. Clinical observations and survival were evaluated throughout lactation. During lactation, feed consumption was measured over 3-day intervals from LD 1 through LD 21 (LDs 1–4, 4–7, 7–10, 10–14, 14–17, 17–21, 21–24, and 24–28).

Select dams and their litters were removed on LD 28 to quantify tris(1-chloro-2-propyl) phosphate plasma concentrations. On LD 28, blood was collected from the retroorbital sinus of randomly selected dams (n = 5/exposure group) and pups (n = 1/sex/exposure group as available). Blood samples were collected in tubes containing tripotassium (K_3_) EDTA and centrifuged, and the plasma was harvested. All samples were stored frozen at approximately −20°C before shipment to MRIGlobal (Kansas City, MO) for analysis.

F_1_ litters were standardized on PND 4 to eight pups per litter, with at least two pups of each sex and a preference for four males and four females each. Litters that did not meet the minimum of eight pups (or had fewer than two pups of either sex) were removed from the study. For continuation of exposure after weaning, two males and two females per litter were randomly selected from 30 (0, 2,500, 5,000, and 20,000 ppm) and 28 (10,000 ppm) litters. Before weaning, on the day the last litter reached PND 26, 25 litters per exposure group were randomly selected and pups (generally two/sex/litter) were randomly assigned to the 2-year study. On the day the last litter reached PND 28, dams were removed from the cages, and the pups were weaned. Weaning marked the beginning of the 2-year study.

After weaning, F_1_ rats were housed two (males) or up to four (females) per cage. Water and dosed feed were available ad libitum. Feed consumption was measured weekly for the first 3 months, then for one 7-day period every 4 weeks thereafter, and at study termination. Cages were changed at least once weekly through PND 4, then changed at least twice weekly. Racks were changed and rotated every 2 weeks. Further details of animal maintenance are given in Table 3.

Two diets were used in the rat studies: (1) NIH-07 during the perinatal phase and (2) NTP-2000 during the postnatal phase. The NIH-07 diet is a higher protein diet that supports reproduction and lactation in rodents, whereas the NTP-2000 diet is a lower protein diet that decreases the incidence of chronic nephropathy in adult rats. Information on feed composition and contaminants for both diets is provided in Appendix B.

### Study Design for Mice

Male and female B6C3F1/N mice were approximately 3 to 4 weeks old upon receipt and were quarantined for 11 (females) or 12 (males) days before study start. Mice were randomly assigned to one of four exposure groups (n = 50 mice/sex/exposure group). Randomization was stratified by body weight that produced similar group mean weights using PATH/TOX SYSTEM software (Xybion Medical Systems Corporation, Lawrenceville, NJ). Mice were fed diets containing 0, 1,250 (males only), 2,500, 5,000, or 10,000 (females only) ppm TCPP for 2 years.

Five male and five female mice were randomly selected for parasite evaluation and gross observation of disease. The health of the mice was monitored during the study according to the protocols of the NTP Sentinel Animal Program (Appendix C). All test results were negative.

Mice were housed individually (males) or up to four (females) per cage. Water and dosed feed were available ad libitum. Feed consumption was measured weekly for the first 3 months, then for one 7-day period every 4 weeks thereafter, and at study termination. Cages were changed at least once weekly (males) or twice weekly (females) and rotated every 2 weeks. Racks were changed and rotated every 2 weeks. Further details of animal maintenance are given in Table 3. Information on feed composition and contaminants is given in Appendix B.

### Clinical Examinations and Pathology

In the 2-year studies in rats and mice, animals were observed twice daily for signs of morbidity and moribundity and were weighed before dosed feed exposure on study day 1, weekly for the first 13 weeks, every 4 weeks thereafter, and at study termination. Clinical observations were recorded every 4 weeks and at study termination.

At the 3-, 6-, 12-, and 18-month interim evaluations, blood was collected from up to 10 predesignated F_1_ rats/sex/exposure group and up to 5 predesignated mice/sex/exposure group for determination of TCPP concentrations. Blood samples were collected from the retroorbital plexus into tubes containing K_3_ EDTA as the anticoagulant (rats) or from the retroorbital sinus into tubes containing EDTA as the anticoagulant (mice). All rats continued on study after blood collection. Following blood collection at each interval, mice were euthanized via carbon dioxide inhalation and disposed of properly without further evaluation. Plasma was isolated from the blood via centrifugation and maintained frozen on dry ice or in liquid nitrogen. Frozen samples were either stored in a freezer set at −85°C to −60°C or shipped immediately following collection. Samples were shipped to MRIGlobal (Kansas City, MO) for analysis.

Complete necropsies and microscopic examinations were performed on all F_1_ rats and all mice. At necropsy, all organs and tissues were examined for grossly visible lesions and all major tissues were fixed and preserved in 10% neutral buffered formalin (NBF) except for eyes, testes, vaginal tunics, and epididymides, which were first fixed in Davidson’s solution or modified Davidson’s solution. Mouse liver tumors >5 mm in diameter were dissected in half and one half was collected in 10% NBF and the other half was snap-frozen in liquid nitrogen and stored at −80°C until processed for a molecular pathology study (Appendix G). Tissues were processed and trimmed, embedded in paraffin, sectioned at a thickness of approximately 5 μm, and stained with H&E for microscopic examination. For all paired organs (e.g., adrenal gland, kidney, ovary), samples from each organ were examined. In F_1_ rats, the uterus, cervix, vagina, and ovaries were mounted on cardstock before placement in fixative. Uterine horns were bisected at their midpoint, and one transverse section was taken from the midpoint of each horn for histopathological evaluation. The uterine body and the two free portions of each uterine horn were also examined. Tissues examined microscopically are listed in Table 3.

Microscopic evaluations were completed by the study laboratory pathologist, and the pathology data were entered into the Toxicology Data Management System. The report, slides, paraffin blocks, residual wet tissues, and pathology data were sent to the NTP Archives for inventory, slide/block match, wet tissue audit, and storage. The slides, individual animal data records, and pathology tables were evaluated by a QA pathologist at a pathology laboratory independent of the study laboratory. The individual animal records and tables were compared for accuracy, the slide and tissue counts were verified, and the histotechnique was evaluated. For the 2-year studies, a QA pathologist evaluated slides from all tumors and all potential target organs, which included the liver of rats and mice; the kidney of rats and male mice; the adrenal gland of rats and mice; the heart, pituitary gland, and thyroid gland of rats; the testis of male rats; the uterus of female rats; and the skin, lymph node, and lung of mice.

The DTT pathologist reviewed and addressed the diagnostic discrepancies between the QA and the laboratory pathologists. The QA pathologist also served as the Pathology Working Group (PWG) coordinator, and in consultation with the DTT pathologist, selected tissues for further review by the PWG. Representative histopathology slides containing examples of lesions related to chemical administration, examples of disagreements in diagnoses between the laboratory and QA pathologists, or lesions of general interest were presented by the coordinator to the PWG for review. The PWG consisted of the DTT pathologist and other pathologists experienced in rodent toxicologic pathology. This group examined the tissues without any knowledge of exposure groups. When the PWG consensus diagnosis differed from that of the laboratory pathologist, the diagnosis was changed. Final diagnoses for reviewed lesions represent a consensus between the laboratory pathologists, reviewing pathologists, DTT pathologist, and the PWG. Details of these review procedures have been described, in part, by Maronpot and Boorman^53^ and Boorman et al.^54^ For subsequent analyses of the pathology data, the decision of whether to evaluate the diagnosed lesions for each tissue type separately or combined was generally based on the guidelines of Brix et al.^55^

## Statistical Methods

For all analyses, p values ≤0.05 were considered statistically significant. Statistical significance is one component of the “weight-of-evidence” approach to evaluate carcinogenicity (described in the Explanation of Levels of Evidence of Carcinogenic Activity section).

### Survival Analyses

The probability of survival was estimated by the product-limit procedure of Kaplan and Meier^57^ and is presented graphically. Animals surviving to the end of the observation period are treated as censored observations, as are animals dying from unnatural causes within the observation period. Animals dying from natural causes are included in analyses and are treated as uncensored observations. For the 2-year mouse study, exposure concentration-related trends are identified with Tarone’s life-table test,^58^ and pairwise exposure concentration-related effects are assessed using Cox’s method.^59^ For the rat perinatal and 2-year study, exposure concentration-related trends and pairwise exposure concentration-related effects on survival are assessed using a Cox proportional hazards model^59^ with a random litter effect. All reported p values for the survival analyses are two-sided.

### Calculation of Incidence

The incidences of neoplasms or nonneoplastic lesions are presented as the numbers of animals bearing such lesions at a specific anatomic site. For calculation of incidence rates, the denominator for most neoplasms and all nonneoplastic lesions is the number of animals for which the site was examined microscopically. When macroscopic examination was required to detect neoplasms in certain tissues (e.g., mesentery, pleura, peripheral nerve, skeletal muscle, tongue, tooth, and Zymbal’s gland) before microscopic evaluation, however, the denominator consists of the number of animals that had a gross abnormality. When neoplasms had multiple potential sites of occurrence (e.g., leukemia or lymphoma), the denominator consists of the number of animals on which a necropsy was performed. Additional study data also give the survival-adjusted neoplasm rate for each group and each site-specific neoplasm. This survival-adjusted rate (based on the Poly-3 method described below) accounts for differential mortality by assigning a reduced risk of neoplasm, proportional to the third power of the fraction of time on study, only to site-specific, lesion-free animals that do not reach terminal euthanasia.

### Analysis of Neoplasm and Nonneoplastic Lesion Incidence

Statistical analyses of neoplasm and nonneoplastic lesion incidence for the 2-year studies considered two features of the data. Some animals did not survive the entire 2 years of the study, so survival differences between groups had to be considered. In addition, for the rat perinatal and 2-year study, up to two animals per sex were randomly selected from each litter to participate in the study. The statistical analysis of lesion incidence used the Poly-3 test to account for survival differences, with a Rao-Scott adjustment for litter effects, as described below.

The Poly-k test^60-62^ was used to assess neoplasm and nonneoplastic lesion prevalence. This test is a survival-adjusted quantal-response procedure that modifies the Cochran-Armitage linear trend test to account for survival differences. More specifically, this method modifies the denominator in the quantal estimate of lesion incidence to approximate more closely the total number of animal years at risk. For analysis of a given site, each animal is assigned a risk weight. This value is 1 if the animal had a lesion at that site or if it survived until terminal euthanasia; if the animal died before terminal euthanasia and did not have a lesion at that site, its risk weight is the fraction of the entire study time that it survived, raised to the kth power.

This method yields a lesion prevalence rate that depends only on the choice of a shape parameter for a Weibull hazard function describing cumulative lesion incidence over time.^60^ Unless otherwise specified, a value of k = 3 was used in the analysis of site-specific lesions. This value was recommended by Bailer and Portier^60^ after an evaluation of neoplasm onset time distributions for a variety of site-specific neoplasms in control Fischer 344 rats and B6C3F1 mice.^63^ Bailer and Portier^60^ showed that the Poly-3 test gave valid results if the true value of k was anywhere in the range of 1 to 5. A further advantage of the Poly-3 method is that it does not require lesion lethality assumptions. Variation introduced by the use of risk weights, which reflect differential mortality, was accommodated by adjusting the variance of the Poly-3 statistic as recommended by Bieler and Williams.^64^ Poly-3 tests used the continuity correction described by Nam.^65^

Littermates tend to be more like each other than like fetuses/pups in other litters. Failure to account for correlation within litters leads to underestimates of variance in statistical tests, resulting in higher probabilities of Type I errors (“false positives”). Because up to two pups/sex/litter were present in the rat perinatal and 2-year study, the Poly-3 test was modified to accommodate litter effects using the Rao-Scott approach.^66^ The Rao-Scott approach accounts for litter effects by estimating the ratio of the variance in the presence of litter effects to the variance in the absence of litter effects. This ratio is then used to adjust the sample size downward to yield the estimated variance in the presence of litter effects. The Rao-Scott approach was implemented in the Poly-3 test as recommended by Fung et al.^67^ formula ₸_RS2_.

Tests of significance included pairwise comparisons of each exposed group with control groups and a test for an overall exposure concentration-related trend. Reported p values are one-sided. The significance of a lower incidence or negative trend in lesions is approximated as 1−p with the letter N added (e.g., p = 0.99 is presented as p = 0.01N). For the rat perinatal and 2-year study, Rao-Scott-adjusted Poly-3 tests were used for trend and pairwise comparisons to the control group. For neoplasms and nonneoplastic lesions observed without litter structure (e.g., the mouse 2-year study), Poly-3 tests that included the continuity correction, but without adjustment for potential litter effects, were used. For the rat perinatal and 3-month study, Rao-Scott-adjusted Cochran-Armitage tests without the Poly-3 adjustment for survival were used.

To evaluate incidence rates by litter in the rat perinatal and 2-year study, the proportions of litters affected by each lesion type were tested among groups. Cochran-Armitage trend tests and Fisher’s exact test^68^ were used to test for trends and pairwise differences from the control group, respectively.

### Analysis of Continuous Variables

Before statistical analysis, outliers identified using the Dixon and Massey test^69^ for small samples (n < 20) and Tukey’s outer fences method^70^ for large samples (n ≥ 20) were examined by DTT personnel, and biologically implausible values (likely due to experimental error) were eliminated from the analysis.

For the mouse 3-month study, organ and body weight measurements, which historically have approximately normal distributions, were analyzed with the parametric multiple comparison procedures of Dunnett^71^ and Williams.^72,73^ Hematology and sperm count data were analyzed using the nonparametric multiple comparison methods of Shirley^74^ [as modified by Williams^75^] and Dunn^76^ given that these endpoints typically have skewed distributions. For all quantitative endpoints, the Jonckheere test^77^ was used to assess the significance of the exposure concentration-related trends and to determine at the 0.01 level of significance, whether a trend-sensitive test (the Williams or Shirley test) was more appropriate for pairwise comparisons than a test that does not assume a monotonic exposure concentration-related trend (the Dunnett or Dunn test).

For the rat perinatal studies, dam gestational and lactational feed consumption, litter sizes, pup survival, and proportion of male pups per litter were analyzed using the nonparametric Shirley or Dunn tests described above. Organ weights, terminal body weights, clinical chemistry, and hematology data were measured on two pups/sex/litter in the rat perinatal studies; more than two pups/sex/litter were possible in preweaning body weight measurements. The analysis of the clinical chemistry and hematology data took litter effects into account using a bootstrapped Jonckheere test for trend and a Datta-Satten^78^ modification to the Wilcoxon test for pairwise comparisons, with a Hommel^79^ adjustment for multiple comparisons. The analyses of pup body weights, organ weights, and body weights adjusted for litter size (described below) of these animals took litter effects into account using a mixed model with litter as a random effect. To adjust for multiple comparisons a Dunnett-Hsu adjustment was used.^80^ Dam body weights during gestation and lactation were analyzed with the parametric multiple comparison procedures of Dunnett^71^ or Williams,^72,73^ depending on whether the Jonckheere test indicated the use of a trend-sensitive test. P values for these analyses are two-sided. For the image analysis of thymus size in the rat perinatal and 3-month study, pairwise comparisons with the control group were performed using one-sided Dunnett tests.

### Analysis of Gestational and Fertility Indices

Cochran-Armitage trend tests were used to test the significance of trends in gestational and fertility indices across exposure groups in the rat perinatal studies. Fisher’s exact test was used to conduct pairwise comparisons of each exposed group with the control group. P values for these analyses are two-sided.

### Body Weight Adjustments

Preweaning pup body weights in the rat perinatal studies were adjusted for live litter size as follows: A linear model was fit to body weights as a function of exposure and litter size. The estimated coefficient of litter size was then used to adjust each pup body weight based on the difference between its litter size and the mean litter size. Prestandardization PND 4 body weights were adjusted for PND 1 litter size, and body weights measured between PND 4 poststandardization and PND 28 were adjusted for PND 4 poststandardization litter size. After adjustment, mean body weights were analyzed with a linear mixed model with a random litter effect.

### Historical Control Data

The concurrent control group is the most valid comparison to the exposed groups and is the only control group analyzed statistically in NTP bioassays. Historical control data are often helpful in interpreting potential exposure concentration-related effects, however, particularly for uncommon or rare neoplasm types. For meaningful comparisons, the conditions for studies in the historical control data must be generally similar. Significant factors affecting the background incidence of neoplasms at a variety of sites are diet, sex, strain/stock, and route of exposure. The NTP historical control database contains all 2-year studies for each species, sex, and strain/stock with histopathology findings in control animals completed within the most recent 5-year period,^81-83^ including the concurrent control for comparison across multiple technical reports. In general, the historical control data for a given study includes studies using the same route of administration, and the overall incidence of neoplasms in controls for all routes of administration are included for comparison, including the current study.

## Quality Assurance Methods

The 3-month and 2-year studies were conducted in compliance with U.S. Food and Drug Administration Good Laboratory Practice Regulations.^84^ In addition, the 3-month and 2-year study reports were audited retrospectively by an independent QA contractor against study records submitted to the NTP Archives. Separate audits covered completeness and accuracy of the pathology data, pathology specimens, final pathology tables, and a draft of this NTP Technical Report. Audit procedures and findings are presented in the reports and are on file at NIEHS. The audit findings were reviewed and assessed by DTT staff, and all comments were resolved or otherwise addressed during the preparation of this Technical Report.

## Genetic Toxicology

The genetic toxicity of TCPP was assessed by testing whether the chemical induces mutations in various strains of Salmonella typhimurium and Escherichia coli or increases the frequency of micronucleated erythrocytes in rat and mouse peripheral blood. The protocol for these studies and the results are given in Appendix D.

The genetic toxicity studies have evolved from an earlier effort to develop a comprehensive database permitting a critical anticipation of a chemical’s carcinogenicity in experimental animals based on numerous considerations, including the relationship between the molecular structure of the chemical and its observed effects in short-term in vitro and in vivo genetic toxicity tests (structure-activity relationships). The short-term tests were developed originally to clarify proposed mechanisms of chemical-induced DNA damage, given the relationship between electrophilicity and mutagenicity,^85^ and the somatic mutation theory of cancer.^86,87^ Not all cancers, however, arise through genotoxic mechanisms.

### Bacterial Mutagenicity

DNA reactivity combined with Salmonella mutagenicity is highly correlated with induction of carcinogenicity in multiple species/sexes of rodents and at multiple tissue sites.^88^ A positive response in the Salmonella test was shown to be the most predictive in vitro indicator for rodent carcinogenicity (89% of the Salmonella mutagens are rodent carcinogens).^89,90^ Additionally, no battery of tests that included the Salmonella test improved predictivity over the Salmonella test alone. Other tests, however, can provide useful information on the types of DNA and chromosomal damage induced by the chemical under investigation.

### Peripheral Blood Micronucleus Test

Micronuclei (literally “small nuclei” or Howell-Jolly bodies) are biomarkers of induced structural or numerical chromosomal alterations and are formed when acentric fragments or whole chromosomes fail to incorporate into either of two daughter nuclei during cell division.^91,92^ Acute in vivo bone marrow chromosome aberration and micronucleus tests appear to be less predictive of carcinogenicity than the Salmonella test.^93,94^ However, clearly positive results in long-term peripheral blood micronucleus tests have high predictivity for rodent carcinogenicity; a weak response in one sex only or negative results in both sexes in this assay do not correlate well with either negative or positive results in rodent carcinogenicity studies.^95^ Because of the theoretical and observed associations between induced genetic damage and adverse effects in somatic and germ cells, determination of in vivo genetic effects is important to overall understanding of the risks associated with exposure to a particular chemical.