# Introduction

## Chemical and Physical Properties

Tris(chloropropyl) phosphate (TCPP) is a clear, colorless, liquid mixture. TCPP has a molar mass of 327.56 g/mol and a relative density of 1.3 g/cm^3^. Estimated/predicted ranges of physical properties for this mixture include: boiling point, 283°C–365°C; vapor pressure, 5.25e-5–3.74e-3 mm Hg; and water solubility,1.58e-4–3.63e-3 mol/L. The experimental log P (octanol:water partition coefficient) of TCPP was determined to be 2.59 and the predicted range is 1.53–2.89.^2-7^

## Production, Use, and Human Exposure

TCPP is produced as an isomeric mixture in a closed system by the reaction of phosphorus oxychloride and propylene oxide to generate a combination of four isomers.^5^ The most abundant isomer in commercial products is tris(1-chloro-2-propyl) phosphate (TCIPP; 50%–85%) (Table 1). Additional isomers include bis(2-chloro-1-methylethyl) 2-chloropropyl phosphate (15%–40%), bis(2-chloropropyl) 2-chloroisopropyl phosphate (<15%), and tris(2-chloropropyl) phosphate (<1%). Variations in manufacturing methods result in commercial formulations that contain different ratios of the four isomers. The TCPP isomeric mixture and commercial products are commonly referred to by the CASRN 13674-84-5, which is the CASRN of the major isomer, TCIPP.^4^

Table 1 Tris(chloropropyl) Phosphate Isomers in Commercial Products

Isomer^a^ | CASRN | Chemical Structure | Percentage (w/w) in Commercial Products
Tris(1-chloro-2-propyl) phosphate 2-Propanol, 1-chloro-, 2,2ʹ,2ʺ-phosphate Tris(2-chloro-1-methylethyl) phosphate Tris(2-chloro isopropyl)phosphate | 13674-84-5 | | 50%–85%
Bis(2-chloro-1-methylethyl) 2-chloropropyl phosphate Bis(1-chloro-2-propyl) 2-chloro-1-propyl phosphate Bis(2-chloro isopropyl) 2-chloropropyl phosphate | 76025-08-6 | | 15%–40%
Bis(2-chloropropyl) 2-chloroisopropyl phosphate 2-Chloro-1methylethylbis(2-chloropropyl) phosphate Bis(2-chloropropyl) 2-chloro-1-methylethyl phosphate Bis(2-chloro-1-propyl) 1-chloro-2-propyl phosphate | 76649-15-5 | | <15%
Tris(2-chloropropyl) phosphate 1-Propanol, 2-chloro-, phosphate (3:1) Tris(2-chloro-1-propyl) phosphate | 6145-73-9 | | <1%

^a^ Tris(chloropropyl) phosphate (TCPP) isomers (in bold, noted by the U.S. Environmental Protection Agency [EPA] Registry Name) and common synonyms listed in the EPA Substance Registry Services database.^10^

The United States manufactured approximately 43 million pounds of TCPP in 2014.^2^ TCPP is used as a flame retardant in textiles, furniture (flexible polyurethane foam), and other related products. In addition, it is manufactured for use in construction materials (rigid polyurethane foam), electronic products, paints, coatings, and adhesives.^3^ TCPP has been proposed as a substitute for brominated flame retardants and as a replacement for other chlorinated flame retardants such as tris(2-chloroethyl) phosphate.^8,9^

It is beyond the scope of this report to summarize all publications and reports on TCPP in various environmental media; however, reports from other agencies thoroughly review TCPP in food, ambient and indoor air, dust, soil and sediment, drinking water, and other media. Environmental fate and transport of TCPP were recently summarized by the U.S. Environmental Protection Agency (EPA) Design for the Environment Branch^4^ and Health Canada.^11^ TCPP is expected to migrate to air and dust after release from industrial sites and wastewater. It is not expected to be highly mobile in soil or water.^12^ Monitoring studies suggest that TCPP is associated with particles in air, which can increase its persistence in the environment.^11^ Limited data from aquatic biota also suggest that TCPP is not bioaccumulative.^11^

The EPA Office of Pollution Prevention and Toxics suggests that exposure to TCPP is likely to occur through inhalation of vapors or particulates and via dermal exposure during the manufacturing or use of consumer products containing TCPP.^3^ Because TCPP is considered ubiquitous in the environment, consumers could be exposed by inhalation of vapors or particulates, direct skin contact, and incidental ingestion. Exposures can occur in offices, homes, and other indoor environments from using consumer products such as upholstered furniture that contains TCPP. Children are considered more susceptible to ingestion of TCPP because of increased object-to-mouth behaviors.^13^ Human exposure to TCPP can be measured using biomarkers of TCPP (both the parent compound and its metabolites). Human biomonitoring studies of TCPP have used urine, serum or plasma, breast milk, hair, placenta, and nails, although urine is the most frequently used matrix. TCPP metabolites measured in urine samples include bis(1-chloro-2-propyl) phosphate (BCIPP or BCPP) and bis(1-chloro-2-propyl) 1-hydroxy-2-propyl phosphate (BCIPHIPP).^14,15^ TCPP, BCPP, and BCIPHIPP have been detected in urine samples in study populations from North America,^16-22^ Europe,^23^ Asia,^24-26^ and Australia.^14,27^ Among these studies, urine has been collected from populations of children, adolescents, mother-child pairs, and adults, and in a variety of settings (e.g., general population, hospital-based, occupational, school/daycare). Concentrations of individual biomarkers vary by population characteristics,^18,28^ including age, sex, and other sociodemographic characteristics including race/ethnicity, and socioeconomic status. The highest reported urinary concentration of BCPP (1,620 µg BCPP/g creatinine) was in a sample from male spray polyurethane foam workers.^16^

## Regulatory Status

TCPP is listed on the EPA Toxic Substances Control Act (TSCA) Inventory. Currently, no regulations restrict production or use of TCPP in the United States, but in 2015, EPA announced plans to further assess the risk to consumers, the general population, and aquatic organisms following exposure to TCPP and similar chemicals.^3^ The U.S. Consumer Product Safety Commission (CPSC) is assessing the risks to consumers’ health and safety from the use of additive, nonpolymeric organohalogen flame retardants, as a class of chemicals, in the following products: (1) durable infant or toddler products, children's toys, childcare articles, or other children's products (other than children's car seats); (2) upholstered furniture sold for use in residences; (3) mattresses and mattress pads; and (4) plastic casings surrounding electronics. TCPP is one of the chemicals under investigation. Final recommendations from this assessment have not been released.

A similar evaluation of organohalogen flame retardants is under investigation by the European Chemicals Agency (ECHA) and other European agencies. TCPP is registered under REACH (Registration, Evaluation, Authorisation, and Restriction of Chemicals).^29^ A 2008 European Union Risk Assessment Report for TCPP indicated no unacceptable risks for workers, consumers, or the general population apart from effects on fertility and developmental toxicity related to dermal exposure to workers manufacturing TCPP.^6^ A 2018 screening report by ECHA identified a risk for children from exposure to tris(2-chloroethyl) phosphate (TCEP), TCPP, and tris(1,3-dichloro-2-propyl) phosphate (TDCPP) childcare articles and residential upholstered furniture. This report recommended that a restriction proposal be prepared.^29^

## Absorption, Distribution, Metabolism, and Excretion

### Experimental Animals

Absorption, distribution, metabolism, and excretion (ADME) data are summarized in the European Union Risk Assessment Report,^6^ the Health Canada Screening Assessment Report,^11^ and the EPA Design for the Environment Report.^4^ These reports, whose findings were based on limited animal studies, indicate that TCPP is readily absorbed and excreted. The literature contains no studies on the toxicokinetics of TCPP in animals.

Briefly, TCPP is readily absorbed and excreted by male Wistar rats following gavage administration of 50 µmol [^14^C]TCPP/kg body weight.^30^ Approximately 98% of the administered dose was recovered during the 168 hours after dosing. Of the administered dose, 67%, 22%, and 7.7% TCPP was recovered in urine, feces, and expired air, respectively, within 48 hours. TCPP was rapidly distributed to tissues, with tissue to blood ratios highest in the liver and kidney followed by lung, spleen, and adipose during the first 12 hours after administration. The elimination half-life in blood, based on total radioactivity, was estimated to be approximately 59 hours. Biliary excretion studies showed that approximately 45% of the administered dose was excreted in bile within 48 hours and that TCPP excreted in feces is likely from biliary excretion.

### Humans

The literature contains no studies on the ADME of TCPP in humans. TCPP metabolism was investigated in vitro with human liver microsomes by Van den Eede et al.^15^ Incubation of microsomes with TCPP resulted in several Phase I metabolites including BCPP, a major metabolite; BCIPHIPP; bis(1-chloro-2-propyl) 1-carboxy-2-propyl phosphate; and 1-chloro-2-propyl,1-hydroxy-2-propyl phosphate. No Phase II metabolites were detected.

## Toxicity

Toxicity data on TCPP, both published and unpublished, have been summarized in reports by the National Industrial Chemicals Notification and Assessment Scheme,^31^ EPA Design for the Environment Branch,^4^ World Health Organization,^9^ Screening Information Dataset (SIDS),^10^ European Union,^6^ Agency for Toxic Substances and Disease Registry,^7^ National Academy of Sciences,^32^ and Health Canada.^11^ It is beyond the scope of this report to discuss all available toxicity data for TCPP; as such, a brief summary of information from the aforementioned reports is provided here with a focus on published peer-reviewed literature.

### Experimental Animals

Reported acute oral median lethal dose (LD_50_) values for TCPP were above 500 mg TCPP/kg body weight (mg/kg) in male rats and 632 mg/kg in female rats of multiple strains, with the majority of values less than 2,000 mg/kg.^5,6,12^ Common clinical observations in acute studies included ataxia, hunched posture, lethargy, labored respiration, increased salivation, body tremors, and piloerection. Macroscopic signs of toxicity included hemorrhagic lungs and dark liver and kidneys. The acute dermal LD_50_ values for Sprague Dawley rats and New Zealand albino rabbits are reported to be >2,000 mg/kg and the inhalation median lethal concentration (LC_50_) in Sprague Dawley rats is >4.6 mg/L.^5,6,12^ The EPA Design for the Environment Branch assigned a low hazard to TCPP for acute toxicity.^4^

In a 13-week toxicity study, Fyrol PCF^®^ (i.e., TCPP) administered in feed to Sprague Dawley rats (20/sex/concentration) at 800 to 20,000 ppm had no effect on survival, clinical observations, hematology, clinical chemistry, or urinalysis parameters compared to the control animals.^33^ Body weights were decreased (approximately 2% compared to control animals) at the highest exposure concentration in male and female rats. Significantly increased absolute and relative liver weights were noted in all exposed male rats and in the two highest exposure groups of female rats (7,500 and 20,000 ppm). Relative kidney weights were increased in male rats in the 7,500 and 20,000 ppm groups compared to the control group. Histopathological evaluation revealed minor changes in the liver, kidney, and thyroid gland, which were most prevalent in the two highest exposure concentration groups. These data informed the EPA Design for the Environment Branch’s decision to assign a moderate hazard to TCPP for repeat-dose toxicity.^4^

### Humans

The literature contains no studies on the toxicity of TCPP in humans.

### Data Mining

In Tox21 (Toxicology in the 21st Century program) in vitro screening assays, TCPP showed activity in 10 endpoints, 7 of which were related to xenobiotic homeostasis, including activation of the pregnane X receptor (PXR) signaling pathway and the constitutive androstane receptor (CAR) pathway, although to a lesser degree than for reference chemicals tested (Appendix E). In a Division of Translational Toxicology (DTT)-sponsored 5-day toxicogenomic study, oral administration of TCPP to male rats resulted in the upregulation of biomarker gene expression in the liver and kidney of male rats (Appendix F). In the rat liver, TCPP activates CAR, PXR, and PPARα pathways, and to a lesser extent may activate the Nrf2 pathway.

## Reproductive and Developmental Toxicity

### Experimental Animals

Summaries of the results of a two-generation reproduction study in Wistar rats exposed to TCPP are presented in various hazard and risk assessment reports.^4,6,11^ Rats (28/sex/concentration) received dosed feed formulated for approximate TCPP doses of 0, 100, 333, or 1,000 mg/kg/day over two generations. Animals were administered feed containing TCPP 10 weeks before mating, during mating, throughout gestation and lactation, and until study termination. No exposure concentration-related clinical observations or mortality were reported in either parental generation. TCPP exposure did not affect precoital time, mating index, fecundity index, fertility index, duration of gestation, or postimplantation loss. The mean number of pups delivered was lower in the F_0_ and F_1_ generations in the 333 and 1,000 mg/kg/day groups compared to the control group. The reported lowest-observed-adverse-effect level (LOAEL) for F_0_ females in these studies was 99 mg/kg/day due to a significant decrease in uterus weights and effects on the estrous cycle. Effects such as decreased body and absolute seminal vesicle weights were observed in F_0_ males exposed to 293 mg/kg/day. F_1_ males and females had LOAELs of 85 and 99 mg/kg/day, respectively. This assignment was based on a significant decrease in kidney weights in males and pituitary weights in females.

Two separate studies suggest that TCPP is not a developmental toxicant in rodents. In 1982, Kawasaki et al.^34^ reported results from a developmental toxicity study in which Wistar rats were fed a diet containing 0%, 0.01%, 0.1%, or 1% TCPP from gestation day (GD) 0 through GD 20 (n = 11 to 14). Daily TCPP intake for the exposed groups was estimated to be 6, 70, or 625 mg/kg/day TCPP, respectively. Following TCPP exposure, no significant effects were observed on maternal toxicity, littering endpoints, or fetal survival. The only identified fetal abnormality was an exposure concentration-related increase in the incidences of cervical ribs and absent 13th ribs. In 2020, NTP reported results from a prenatal developmental toxicity of TCPP.^35^ In these studies, time-mated female Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) rats received TCPP by gavage on GD 6 (expected implantation) to the day before expected parturition (GD 20). The test lot of TCPP was also used in the current NTP 3-month subchronic toxicity studies in rats and mice. Rats were administered 0, 162.5, 325, or 650 mg/kg/day of TCPP following evidence of maternal toxicity at 1,000 mg/kg/day in a dose range-finding study. Under the conditions of the study, there was no evidence of developmental toxicity observed. Unlike the Kawasaki study, NTP found no biologically relevant exposure-related malformations during external, visceral, or skeletal fetal exams of rats exposed to TCPP.

Toxicity studies evaluating the developmental and neurodevelopmental toxicity of TCPP are also available in the embryonic zebrafish model.^32^ Overall, the data from these studies suggest that TCPP is not teratogenic or overtly toxic compared with other flame retardants.^36-39^

### Humans

Associations among flame-retardant exposure and effects on human reproductive or developmental toxicity have been suggested from epidemiological studies.^40-44^ However, a strong association with adverse effects on reproductive or developmental toxicity in humans has not yet been determined for TCPP or its metabolites.

## Carcinogenicity

### Experimental Animals

The literature contains no studies on the carcinogenicity of TCPP in experimental animal models. Health Canada summarized recent activities to assess the carcinogenic potential of TCPP through read-across approaches with the structurally similar flame retardant, TCEP.^11,45^ The evidence suggested that TCPP may be carcinogenic in rodents.

### Humans

Only two observational epidemiology studies were identified that examined measured TCPP metabolites and papillary thyroid cancer, both with null findings. A population-based case-control study of 200 U.S. women found no association between either urinary concentration of BCIPP or BCIPHIPP and papillary thyroid cancer.^46^ A hospital-based case-control study of 140 U.S. women found no association between TCIPP measured in household dust and papillary thyroid cancer.^47^

## Genetic Toxicity

Few peer-reviewed publications reporting on the genetic toxicity of TCPP were identified in the literature. Results from all reported bacterial mutation assays, in which TCPP was tested in several different strains with and without induced male rat or hamster liver S9, were negative.^48-50^ Negative results also were reported for TCPP in an in vitro rat hepatocyte DNA repair test^51^ and in an in vitro comet assay for DNA damage in hamster V79 cells that was conducted with and without induced rat liver S9.^48^ The literature contains no studies on the genetic toxicity of TCPP in in vivo models.

## Study Rationale

CPSC nominated TCPP because its use as a flame retardant for flexible polyurethane foam in home furnishings and construction materials is expected to increase.^52^ Exposure of consumers to TCPP via oral, dermal, and inhalation routes was also expected to increase, and, at the time of nomination, publicly available toxicity data from long-term exposure were considered limited. CPSC therefore requested subchronic and chronic oral studies in rats and/or mice. Exposure through feed was selected to mimic intermittent human exposure through accidental ingestion from dust, food, and water sources. Exposure to the isomeric mixture, rather than an individual isomer of TCPP, was also chosen to best represent human exposure.