# Appendix H Supplemental Data

Tables with supplemental data can be found here: https://doi.org/10.22427/NTP-DATA-TR-602.

## H.1 Perinatal and Three-month Study – Rats

### H.1.1 Data Tables

Adjusted Pup Body Weights

E03 – Growth Curves

E04 – Mean Body Weights and Survival Table

E05 – Clinical Observations Summary

E06 – Mean Feed Consumption by Treatment Group

E08 – Feed and Compound Consumption Table

Gestational Body Weights

Gestational and Lactational Chemical Consumption

Gestational and Lactational Food Consumption

Image Analysis of Thymus Size for Male and Female Rats

Lactational Body Weights

P03 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site

P04 – Neoplasms by Individual Animal

P05 – Incidence Rates of Neoplasms by Anatomic Site (Systemic Lesions Abridged)

P09 – Non-Neoplastic Lesions by Individual Animal

P10 – Statistical Analysis of Non-Neoplastic Lesions

P14 – Individual Animal Pathology Data

P18 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site with Average Severity Grades

PA06 – Organ Weights Summary

PA41 – Clinical Chemistry Summary

PA43 – Hematology Summary

PND 1 Litter and Pup Body Weight Data

PND 4-21 Live Litter Size and Survival

R02 – Reproductive Performance Summary

R06 – Andrology Summary

### H.1.2 Individual Animal Data

Female Individual Animal Body Weight Data

Female Individual Animal Clinical Observations

Female Individual Animal Non-Neoplastic Pathology Data

Female Individual Animal Survival

Female Individual Animal Terminal Body Weight Data

Male Individual Animal Body Weight

Male Individual Animal Clinical Observations

Male Individual Animal Non-Neoplastic Pathology Data

Male Individual Animal Survival

Male Individual Animal Terminal Body Weight Data

Individual Animal Andrology Data

Individual Animal Body Weight Data F1 Post Wean

Individual Animal Clinical Chemistry Data

Individual Animal Clinical Observation Data F1 Post Wean

Individual Animal DamID and PupID Data

Individual Animal Food Consumption Data F1 Post Wean

Individual Animal Gross Pathology Data F1

Individual Animal Hematology Data

Individual Animal Histo Pathology Data F1

Individual Animal Organ Weight Data

Individual Animal Removal Reasons Data

Individual Animal Reproductive Performance Data

## H.2 Three-month Study – Mice

### H.2.1 Data Tables

E03 – Growth Curves

E04 – Mean Body Weights and Survival Table

E05 – Clinical Observations Summary

E06 – Mean Feed Consumption by Treatment Group

E08 – Feed and Compound Consumption Table

P03 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site

P04 – Neoplasms by Individual Animal

P05 – Incidence Rates of Neoplasms by Anatomic Site (Systemic Lesions Abridged)

P09 – Non-Neoplastic Lesions by Individual Animal

P10 – Statistical Analysis of Non-Neoplastic Lesions

P14 – Individual Animal Pathology Data

P18 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site with Average Severity Grades

PA06 – Organ Weights Summary

PA43 – Hematology Summary

R06 – Andrology Summary

### H.2.2 Individual Animal Data

Female Individual Animal Body Weight Data

Female Individual Animal Non-Neoplastic Pathology Data

Female Individual Animal Survival Data

Female Individual Animal Terminal Body Weight Data

Male Individual Animal Body Weight Data

Male Individual Animal Non-Neoplastic Pathology Data

Male Individual Animal Survival Data

Male Individual Animal Terminal Body Weight Data

Individual Animal Andrology Data

Individual Animal Hematology Data

Individual Animal Organ Weight Data

## H.3 Perinatal and Two-year Study – Rats

### H.3.1 Data Tables

Adjusted Pup Body Weights

E01 – Animal Removal Summary by Treatment Group – Dam Gestation

E01 – Animal Removal Summary by Treatment Group – Dam Lactation

E01 – Animal Removal Summary by Treatment Group – Female Pup

E01 – Animal Removal Summary by Treatment Group – Male Pup

E01 – Animal Removal Summary by Treatment Group

E02 – Animals Removed from Experiment

E02 – Animals Removed from Experiment – Dam Gestation

E02 – Animals Removed from Experiment – Dam Lactation

E02 – Animals Removed from Experiment – Female Pup

E02 – Animals Removed from Experiment – Male Pup

E03 – Growth Curves

E03 – Growth Curves – Dam Gestation

E03 – Growth Curves – Dam Lactation

E03 – Growth Curves – Female Pup

E03 – Growth Curves – Male Pup

E04 – Mean Body Weights and Survival Table

E05 – Clinical Observations Summary

E06 – Mean Feed Consumption by Treatment Group

E08 – Feed and Compound Consumption Table

E12 – Animal History

E12 – Animal History – Dam Gestation

E12 – Animal History – Dam Lactation

E12 – Animal History – Female Pup

E12 – Animal History – Male Pup

Gestational Body Weights

Gestational and Lactational Chemical Consumption

Gestational and Lactational Food Consumption

I05 – Clinical Observation Summary

Lactational Body Weights

P02 – Incidence Rates of Neoplasms by Anatomic Site

P03 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site

P04 – Neoplasms by Individual Animal

P05 – Incidence Rates of Neoplasms by Anatomic Site (Systemic Lesions Abridged)

P08 – Statistical Analysis of Primary Tumors

P09 – Non-Neoplastic Lesions by Individual Animal

P10 – Statistical Analysis of Non-Neoplastic Lesions

P11 – Statistical Analysis of Survival Data

P14 – Individual Animal Pathology Data

P17 – Neoplasms by Individual Animal (Systemic Lesions Abridged)

P18 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site with Average Severity Grades

P40 – Survival Curves

PA48 – Summary of Tissue Concentration

PND 1 Litter Size and Pup Body Weight Data

PND 4-28 Live Litter Size and Survival

R02 – Reproductive Performance Summary

### H.3.2 Individual Animal Data

Female Individual Animal Body Weight Data

Female Individual Animal Body Weight Data All Animals – Dam Gestation

Female Individual Animal Body Weight Data All Animals – Dam Lactation

Female Individual Animal Body Weight Data All Animals – Female Pup

Female Individual Animal Neoplastic Pathology Data

Female Individual Animal Non-Neoplastic Pathology Data

Female Individual Animal Survival

Female Individual Animal Survival Data – Female Pup

Female Individual Animal Survival Data – Female Pup – Dam Gestation

Female Individual Animal Survival Data – Female Pup – Dam Lactation

Female Individual Animal Terminal Body Weight Data

Female Individual Animal Terminal Body Weight Data – Dam Lactation

Female Individual Animal Terminal Body Weight Data – Female Pup

Female Individual Animal Terminal Body Weight Data – Female Pup – Dam Gestation

Female Individual Body Weight All Animals

Female Individual Clinical Observations

Male Individual Animal Body Weight Data All Animals – Male Pup

Male Individual Animal Neoplastic Pathology Data

Male Individual Animal Non-Neoplastic Pathology Data

Male Individual Animal Survival

Male Individual Animal Survival Data – Male Pup

Male Individual Animal Terminal Body Weight Data

Male Individual Animal Terminal_Body Weight Data – Male Pup

Male Individual Body Weight

Male Individual Body Weight All Animals

Male Individual Clinical Observations

Individual Animal Clinical Observations Data

Individual Animal DamID and PupID Data

Individual Animal Reproductive Performance Data

Individual Animal Tissue Concentration Data

Individual Pup Census and Litter Weight by Sex Data

## H.4 Two-year Study – Mice

### H.4.1 Data Tables

E01 – Animal Removal Summary by Treatment Group

E02 – Animals Removed from Experiment

E03 – Growth Curves

E04 – Mean Body Weights and Survival Table

E05 – Clinical Observations Summary

E06 – Mean Feed Consumption by Treatment Group

E08 – Feed Water and Compound Consumption Table

E12 – Animal History

P02 – Incidence Rates of Neoplasms by Anatomic Site

P03 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site

P04 – Neoplasms by Individual Animal

P05 – Incidence Rates of Neoplasms by Anatomic Site (Systemic Lesions Abridged)

P08 – Statistical Analysis of Primary Tumors

P09 – Non-Neoplastic Lesions by Individual Animal

P10 – Statistical Analysis of Non-Neoplastic Lesions

P11 – Statistical Analysis of Survival Data

P14 – Individual Animal Pathology Data

P17 – Neoplasms by Individual Animal (Systemic Lesions Abridged)

P18 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site with Average Severity Grades

P40 – Survival Curves

PA48 – Summary of Tissue Concentration

### H.4.2 Individual Animal Data

Female Individual Animal Body Weight Data All Animals

Female Individual Animal Clinical Observations

Female Individual Animal Neoplastic Pathology Data

Female Individual Animal Non-Neoplastic Pathology Data

Female Individual Animal Survival Data

Female Individual Animal Terminal Body Weight Data

Male Individual Animal Body Weight Data All Animals

Male Individual Animal Clinical Observations

Male Individual Animal Neoplastic Pathology Data

Male Individual Animal Non-Neoplastic Pathology Data

Male Individual Animal Survival Data

Male Individual Animal Terminal_Body Weight Data

## H.5 Genetic Toxicology

### H.5.1 In Vivo Peripheral Blood Micronucleus Study G20263 in Harlan Sprague Dawley Rats

G04 – In Vivo Micronucleus Summary Data

Individual Animal In Vivo Micronucleus Data

### H.5.2 In Vivo Peripheral Blood Micronucleus Study G20263B in B6C3F1 Mice

G04 – In Vivo Micronucleus Summary Data

Individual Animal In Vivo Micronucleus Data

### H.5.3 Salmonella typhimurium (TA98, TA100) and Escherichia coli WP2 uvrA (pKM101) Mutagenicity or Ames Test Study G20263C

G06 – Ames Summary Data

### H.5.4 Salmonella typhimurium (TA97, TA98, TA100, TA1535, TA1537) Mutagenicity or Ames Test Study 815918

G06 – Ames Summary Data

### H.5.5 Toxicogenomics and Multiomics

Up-regulated Gene Results for TCPP and Prototype Chemicals