# Appendix G Multiomics Evaluation of B6C3F1/N Mouse Hepatocellular Carcinomas Arising Spontaneously or Following Chronic Exposure to Tris(chloropropyl) Phosphate

## G.1 Introduction

The National Toxicology Program (NTP) has integrated diverse data sources derived from experimental systems with varying biological complexity to understand the mechanisms of toxicity and carcinogenicity induced by the isomeric mixture of tris(chloropropyl) phosphate (TCPP). These diverse data sources include quantitative high-throughput in vitro screening (qHTS) data, short-term toxicogenomic data, and next-generation sequencing (NGS) data of the mouse liver tumors. This appendix summarizes the NGS data on mouse hepatocellular carcinomas (HCCs) arising spontaneously or following chronic exposure to TCPP.

HCC is the third leading cause of cancer-related death in humans across the world.^159^ It is also the most common primary liver tumor in B6C3F1/N mice and may arise either spontaneously or due to chronic chemical exposure, and male mice have twice the incidence rate compared with female mice.^160^ Hepatocellular carcinogenesis is a multistep process and chemical exposure can modulate the pathogenesis. Genetic and epigenetic alterations that progressively accumulate over a lifetime can contribute to various stages in the carcinogenic process.^161^ Assessment of molecular alterations in rodent HCCs from vehicle control and chemical-exposed experimental animals can provide some insight into the mechanisms of chemical-induced carcinogenesis.^160^

Current developments in sequencing technologies have dramatically changed the field of genomics research. NGS encompasses different techniques, such as whole-genome/exome sequencing, RNA sequencing (RNA-seq), and miRNA sequencing (miRNA-seq). Integrated analytic approaches applied to one or more data platforms (whole-exome sequencing, DNA copy number analyses, DNA methylation, RNA, miRNA, and proteomic expression) can provide a better understanding of the carcinogenic process.^162,163^

## G.2 Materials and Methods

### G.2.1 Multiomics Analyses on Mouse Hepatocellular Carcinomas Arising Spontaneously or Following Chronic Exposure to Tris(chloropropyl) Phosphate

#### G.2.1.1 Animals and Tissue Sampling

HCCs arising either spontaneously or following chemical exposure in B6C3F1/N mice were obtained from the current TCPP 2-year bioassay. HCCs from male mice exposed for 2 years via feed dosed with 1,250 ppm (n = 5) or 5,000 ppm (n = 5) of TCPP (Table G-1) were selected for this study. Samples of nontumor livers and spontaneous HCCs from age-matched mice were obtained from the current study or other NTP studies run within the last 10 years. At necropsy, liver tumors larger than 0.5 mm were flash frozen in liquid nitrogen and stored at −80°C until DNA/RNA isolation. The morphology of liver tumor samples selected for molecular analyses was confirmed independently by two board-certified pathologists. Male B6C3F1/N mouse samples of HCC from TCPP-exposed mice (n = 10), spontaneous HCCs (n = 21), and age-matched nontumor livers from vehicle control groups (n = 10) were included in the molecular analyses.

Table G-1 Summary of Hepatocellular Carcinomas and Nontumor Liver Samples from B6C3F1/N Male Mice in the Two-year Feed Study of Tris(chloropropyl) Phosphate and Nontumor Liver Samples from Male Mice in Two-year Feed Studies

TCPP Exposure Concentration (ppm) | n | HCC Type
0 | 10^a^ | Nontumor tissue
0 | 21^b^ | Spontaneous
1,250 | 5^c^ | TCPP exposed
5,000 | 5^c^ | TCPP exposed

TCPP = tris(chloropropyl) phosphate; n = the number of mice from which tissue was collected; HCC = hepatocellular carcinoma.

^a^ Studies from which animal tissues were sourced, presented as technical report (TR) number (year animals began on study): TR-542 (2001),^164^ TR-558 (2003),^165^ TR-578 (2005),^166^ TR-581 (2006),^167^ and TR-582 (2005).^168^

^b^ Studies from which animal tissues were sourced: TR-443 (1989),^169^ TR-476 (1992),^170^ TR-494 (1994),^171^ TR-549 (2001),^172^ TR-583 (2006),^173^ TR-589 (2008),^174^ TR-594 (2011),^175^ TR-600 (2010),^176^ and TR-602 (2011).^177^

^c^ Study from which animal tissues were sourced: TR-602 (2011).^177^

#### G.2.1.2 DNA Extraction, Whole-exome Sequencing, and Variant Calling

Genomic DNA was extracted and purified using a Puregene Gentra Kit (Qiagen, Valencia, CA). Exome-enriched genomic libraries were prepared from all 41 collected samples (Table G-1) using the SureSelectXT Mouse All Exon kit (Agilent, CA) following the manufacturer’s recommendations with an input of 1 µg DNA. Sequencing was performed on the Illumina HiSeq 2500 at LabCorp (Seattle, WA). Paired-end whole-exome sequencing data were assessed with FastQC (v.0.11.5) for quality control, and sequencing adapters were trimmed with Cutadapt (v.1.12). The short reads were aligned with the Burrows-Wheeler Alignment (BWA) tool with maximal exact matches^178^ against reference mouse genome (mm10). Alignment bam files have gone through base calling quality recalibration with the GATK toolkit.^162^ Variant calling was accomplished by Mutect2 tumor-only mode and against an in-house panel of normal single nucleotide variants (SNV; genomic sequence in vehicle control mice used as a filter) informed by the age-matched nontumor liver samples. Known germline mutations obtained from an in-house whole-genome sequencing project (data not shown) and a mm10 dbSNP database were also excluded. A mutation was only called if it was within the captured regions of 100 base pairs (bp) upstream and downstream of the target exon regions. Only Mutect2 PASS SNVs were reported.

#### G.2.1.3 RNA Isolation, RNA Sequencing, miRNA Sequencing, and Gene Expression Analysis

Total RNA was extracted using miRNeasy Mini Kit (Qiagen, Valencia, CA). RNA integrity was measured with Tapestation (Agilent Technologies, Santa Clara, CA) and all samples had an RNA integrity number (RIN) >7. RNA-seq libraries were prepared for 22 samples (TCPP-exposed HCCs [n = 5], spontaneous HCCs [n = 11], and age-matched nontumor livers from vehicle control mice [n = 6]) (Table G-1) by following the TruSeq Stranded Total RNA Library Prep Gold Kit (Illumina, San Diego, CA) manufacturer’s protocol with an input of 250 ng total RNA. The libraries were sequenced on the Illumina NovaSeq system at the National Institute of Environmental Health Sciences (NIEHS) Epigenomics and DNA Sequencing core facility (Durham, NC).

Raw reads (stranded, 151 bp, paired-end) were first filtered with a custom Perl script to remove reads of average quality score of ≤20, and then processed using the Cutadapt (v.1.12)^179^ program to remove adapter sequences. Mouse nucleotide sequences of all transcripts were retrieved from GENCODE release M23.^180-182^ The mapping-based mode of the Salmon (v1.0.0)^183^ tool was deployed for fast transcript quantification from RNA-seq data to the reference mouse genome (mm10). The quantified transcripts were imported using the R package tximport^184^ and also summarized to gene level with countsFromAbundance = “lengthScaledTPM.” Differential transcript and/or gene expression between TCPP-exposed or spontaneous HCC samples and the control samples was analyzed using Limma-Voom procedure (R package limma, v3.42.2).^185-187^ Genes were considered differentially expressed at an absolute fold-change of two using a false-discovery rate (FDR) adjusted p value (or q value) of 0.05 and AvgExpr more than 0 threshold.

miRNA-seq libraries were prepared for all 41 samples (Table G-1) by following the NEXTFLEX Small RNA-Seq Kit v3 (PerkinElmer Applied Genomics, Waltham, MA) manufacturer’s protocol with an input of 1 µg total RNA. The library preparation was sequenced on the Illumina NextSeq system at the NIEHS Epigenomics and DNA Sequencing core facility (Durham, NC).

FastQC software was used to assess overall sequencing quality.^188^ Unique molecular identifiers (UMI) were extracted using the UMI-tools software.^189^ Reads were aligned to the mm10 genome with the STAR aligner v.2.6.0.^190^ Mouse miRNAs and coordinates were obtained from the miRBase repository.^191^ The featureCounts utility from the Subread package was used to assign reads to miRNAs with -M and -R flags set to detect multimapped (e.g., same alignment position and UMI) and unassigned reads, respectively.^192^ The samtools view function was subsequently used to discard unassigned reads and duplicates were removed with UMI-tools dedup.^193^ Final UMI counts per miRNA were quantified with featureCounts.^192^ The DESeq2 R package v.1.26 was used to detect differentially expressed miRNAs. Genes were considered differentially expressed at an absolute fold-change of two using a 0.01 FDR threshold.^194^

#### G.2.1.4 Mutational Signature Analysis and Cancer Driver Gene Analysis

The MutationalPatterns v.3.2.0 R package^195^ was used to identify mutational processes^196^ by fitting the mutational signatures published in the Catalogue of Somatic Mutations in Cancer (COSMIC) catalog2 to the mutational profiles of the somatic SNVs in each tumor (https://cancer.sanger.ac.uk/signatures/). The latter were obtained by classifying SNVs into 96 categories according to six different possible base-pair substitutions: C > A, C > G, C > T, T > A, T > C, and T > G (interpreting the pyrimidine base in the Watson–Crick pair as the reference base and the bases immediately 5′ and 3′ to the mutated base in the reference genome).^196^ Fitting of mutational signatures to somatic variants was initially performed using all 60 published COSMIC signatures. SnpEff was used to predict and annotate the effects of variants on genes.^197^ Substitutions were selected that altered coding sequence: missense, synonymous, splice site mutations, start lost/gained, or stop lost/gained substitutions. Raw sequence read data were uploaded to the National Center for Biotechnology Information Sequence Read Archive (accession: PRJNA779957).

#### G.2.1.5 Functional Enrichment Analysis of Genes

To identify the biological function of the differentially expressed genes and related toxicity difference between TCPP-exposed HCCs and spontaneous HCCs, Toxicity Lists (Tox Lists) analysis was performed using Ingenuity pathway analysis (IPA) (QIAGEN Ingenuity Systems, Redwood City, CA). Tox Lists are sets of molecules that are known to be involved in particular types of toxicological pathways.

### G.2.2 Statistical Analysis

Fisher’s exact test was conducted to test for significant differences in the number of mutations between TCPP-exposed HCCs and spontaneous HCCs. Plots were created using R^198^ with packages ggplot2, pheatmap, and VennDiagram.

## G.3 Results

### G.3.1 Comparison of the Mutation Landscape between Hepatocellular Carcinomas Arising Spontaneously or Following Tris(chloropropyl) Phosphate Exposure

In male mice, the mutation burden of HCCs arising spontaneously was compared with exposure to low dose (1,250 ppm) and high dose (5,000 ppm) of TCPP. On average, the sequence depth for the whole-exome sequencing was approximately 150-fold. There were no differences in mutation burden between HCCs arising spontaneously and following chronic TCPP exposure (Figure G-1). In addition, there were no differences in mutation burden between the highest (5,000 ppm) and the lowest (1,250 ppm) TCPP exposures.

Figure G-1

Mutation Burden of Hepatocellular Carcinomas in B6C3F1/N Male Mice Arising Spontaneously or Following Chronic (Two-year) Exposure to Tris(chloropropyl) Phosphate

HCC = hepatocellular carcinoma; TCPP-exposed HCC = HCC following tris(chloropropyl) phosphate exposure; High = 5,000 mg TCPP/kg body weight/day (mg/kg/day); Low = 1,250 mg/kg/day.

To determine whether TCPP might preferentially induce mutations in specific nucleotides, mutational spectra were generated according to the trinucleotide context as described in the methods section of this appendix. The nonnegative matrix factorization plots (Figure G-2) show that the mutation spectra for HCCs arising spontaneously or following chronic high or low TCPP exposure were similar to each other, mainly showing C > T or G > A transitions. A cosine correlation similarity was used as a measure of closeness between human COSMIC signature and the mutational spectra of HCCs arising spontaneously or due to chronic TCPP exposure. Three signatures were identified with a cosine similarity higher than 0.70 with a COSMIC signature; the best COSMIC signature matches were SBS5 in TCPP-exposed HCCs and spontaneous HCCs, and SBS40 and SBS3 in TCPP-exposed HCCs (Table G-2). In human cancers, SBS40 and SBS5 are considered clock-like signatures and are correlated with the patient’s age.^199^ SBS3 has been suggested to indicate defective homologous recombination-based DNA damage repair.^199^

In addition to the mutation signatures, mutations in cancer driver genes were documented that identify biological pathways that promote cancer. Hras, Ube2c, Sfr1, and Muc4 were found to be highly mutated in both TCPP-exposed HCCs and spontaneous HCCs. The most frequently mutated genes are indicated in Figure G-3. Interestingly, Ctnnb1 was highly mutated only in spontaneous HCCs but not in TCPP-exposed HCCs.

Figure G-2

Mutational Spectra of Hepatocellular Carcinomas in B6C3F1/N Male Mice Arising Spontaneously or Following Chronic (Two-year) Exposure to Tris(chloropropyl) Phosphate

C = cytosine; A = adenine; G = guanine; T = thymine; HCC = hepatocellular carcinoma; TCPP-exposed HCC = HCC following tris(chloropropyl) phosphate exposure.

Table G-2 Comparison of Mutational Spectra of Spontaneous and Tris(chloropropyl) Phosphate-exposed Hepatocellular Carcinomas in B6C3F1/N Male Mice from the Two-year Study to Human Signatures

COSMIC Signature Best Match | Cosine Similarity
COSMIC Signature Best Match | Spontaneous HCC | TCPP-exposed HCC
SBS5 | 0.713609169 | 0.82649
SBS40 | 0.689305018 | 0.766232
SBS3 | 0.595527185 | 0.705439
SBS89 | 0.550977772 | 0.662781
SBS25 | 0.548747391 | 0.625432
SBS6 | 0.58110974 | 0.619277
SBS32 | 0.587950468 | 0.61254
SBS42 | 0.467218617 | 0.601773
SBS30 | 0.492207486 | 0.577837
SBS44 | 0.463672159 | 0.569612
SBS11 | 0.531883449 | 0.551167
SBS84 | 0.406918893 | 0.508751
SBS15 | 0.523454849 | 0.504139
SBS23 | 0.42163454 | 0.500457
SBS87 | 0.45417571 | 0.498804

COSMIC = Catalogue of Somatic Mutations in Cancer; HCC = hepatocellular carcinomas; TCPP-exposed HCC = HCC following tris(chloropropyl) phosphate exposure.

Figure G-3

Most Frequently Mutated Genes in Hepatocellular Carcinomas in B6C3F1/N Male Mice

This list shows results for hepatocellular carcinomas (A) arising spontaneously or (B) following chronic (2-year) exposure to tris(chloropropyl) phosphate.

### G.3.2 Gene Expression Profiling and Functional Enrichment Analysis

Genome-wide gene expression profiling of 21 samples was performed to identify genes that were differentially expressed across different groups. Principal component analysis (PCA) of mouse mRNA expression profiles demonstrated spontaneous HCC and TCPP-exposed HCCs clustered separately from age-matched vehicle control nontumor liver (Figure G-4A). As seen in the unsupervised hierarchical clustering analysis of the transcriptomic data, the gene expression patterns were similar in HCCs arising spontaneously or following chronic TCPP exposure (Figure G-4B). The PCA indicates the tumor heterogeneity in HCCs arising spontaneously or following chronic TCPP exposure. HCCs arising spontaneously or following chronic TCPP exposure had 789 or 173 uniquely altered genes, respectively, and 1,295 differentially altered genes in common (Figure G-4C).

Figure G-4

Differential Gene Expression Profiles of Hepatocellular Carcinomas in B6C3F1/N Male Mice Arising Spontaneously or Following Chronic (Two-year) Exposure to Tris(chloropropyl) Phosphate

A) A principal components analysis (PCA) (dark blue = vehicle control nontumor liver; orange = spontaneous hepatocellular carcinomas (HCCs); green = HCCs from TCPP-exposed mice. B) A hierarchical cluster analysis showing the comparable gene expression changes in HCCs arising spontaneously or following TCPP exposure. C) Venn diagram showing the number of common or differentially expressed genes that are unique to HCCs arising spontaneously or due to TCPP exposure. HCC = hepatocellular carcinoma; TCPP-exposed HCC = HCC following tris(chloropropyl) phosphate exposure.

To link the biological function of the differentially expressed genes to TCPP-exposed HCCs, Tox Lists analysis in IPA was performed. Pathways related to the development of HCCs included liver hyperplasia and/or hyperproliferation, aryl hydrocarbon receptor (AhR) signaling, lipopolysaccharide and interleukin-1 (LPS/IL-1)-mediated inhibition of retinoid x receptor (RXR) function, xenobiotic metabolism signaling, and hepatic fibrosis; these pathways were common to both HCCs arising spontaneously or following chronic TCPP exposure. Top unique Toxicity List (pathways) altered in HCCs arising spontaneously or following exposure to TCPP were related to fatty acid metabolism and liver proliferation, respectively (Figure G-5).

Figure G-5

Top 10 Tox Lists Derived from Ingenuity Pathway Analysis of Hepatocellular Carcinomas in B6C3F1/N Male Mice Arising Spontaneously or Following Chronic (Two-year) Exposure to Tris(chloropropyl) Phosphate

LPS/IL-1 = lipopolysaccharide/interleukin-1; RXR = retinoid X receptor; LXR = liver X receptor; NRF2 = nuclear factor-erythroid factor 2-related factor 2; FXR = farnesoid X receptor; RAR = retinoic acid receptor; HCC = hepatocellular carcinoma; TCPP-exposed HCC = HCC following tris(chloropropyl) phosphate exposure.

### G.3.3 miRNA Expression Profiles

Differentially expressed miRNA profiles of HCCs arising spontaneously or following chronic TCPP exposure relative to age-matched vehicle control nontumor liver tissue were examined. PCA of mouse global miRNA expression profiles demonstrated spontaneous HCC and TCPP-exposed HCCs clustered separate from age-matched vehicle control nontumor liver (Figure G-6A). The unsupervised hierarchical clustering analysis of miRNA expression showed similar patterns for both HCCs arising spontaneously or following chronic TCPP exposure (Figure G-6B). HCCs arising spontaneously or following chronic TCPP exposure had 49 and 17 miRNA uniquely altered, respectively, and had 128 differentially altered miRNA in common (Figure G-6C).

Figure G-6

Differential miRNA Expression Profiles of Hepatocellular Carcinomas in B6C3F1/N Male Mice Arising Spontaneously or Following Chronic (Two-year) Exposure to Tris(chloropropyl) Phosphate

A) A principal components analysis (PCA) (blue = vehicle control nontumor liver tissue; orange = spontaneous hepatocellular carcinomas (HCCs); green = TCPP-exposed HCCs). B) A hierarchical cluster analysis showing the comparable miRNA alterations in HCCs arising spontaneously or following TCPP exposure. C) Venn diagram showing the number of common or differentially expressed miRNA that are unique to spontaneous HCCs and/or TCPP-exposed HCCs. TCPP-exposed HCC = HCC following tris(chloropropyl) phosphate exposure.

## G.4 Summary

Conclusions from NTP animal studies and bacterial assays have determined that TCPP is largely nongenotoxic (e.g., negative Ames assay, micronucleus assay in male and female rats, and micronucleus assay in female mice; equivocal micronucleus test in male mice) (Appendix H); thus, TCPP likely does not directly cause mutations and initiate carcinogenesis. The evaluation of NGS data on B6C3F1/N mouse HCCs suggested that the mutation burden and mutation spectrum of TCPP-exposed HCCs were similar to spontaneous HCCs. Additional mutation signatures (SBS3 and SBS40) in TCPP-exposed HCCs may reflect additional genetic events related to tumor promotion, such as deficits in DNA damage repair, but further studies are needed to confirm this hypothesis. The cancer driver genes identified in this study were common to both HCCs arising spontaneously or following chronic TCPP exposure. The homologues of Hras, Muc4, and Ctnnb1 are also cancer driver genes in human cancers. The lack of enrichment for Ctnnb1 mutations in TCPP-exposed HCCs compared with spontaneous HCCs suggest that TCPP may not be a strong CAR or PXR activator compared with ginkgo biloba extract^200^ or phenobarbital^201^ given that there were higher frequencies of Ctnnb1 mutations in mouse HCCs from these exposures. The gene expression pattern and miRNA expression pattern of TCPP-exposed HCCs were also similar to spontaneous HCCs and the Toxicity List (pathways) of TCPP-exposed HCCs and spontaneous HCCs analyzed in IPA were comparable. The differentially expressed genes and miRNAs that are unique to TCPP-exposed HCCs may be considered as potential biomarkers to distinguish TCPP-exposed HCCs from spontaneous HCCs; however, further validation by reverse transcription polymerase chain reaction (RT-PCR) is pending. The differential gene expression data suggest that TCPP may act as a tumor promoter by weakly interacting with multiple nuclear receptors such as CAR, PXR, PPARα, AhR, and RXR in rodent hepatocellular carcinogenesis.^202-204^ Further validation and mechanistic studies are needed, however, to confirm their definitive roles in TCPP-induced hepatocellular carcinogenesis.