# Appendix F Five-day Rat Toxicogenomic Study of Tris(chloropropyl) Phosphate

## F.1 Introduction

The National Toxicology Program (NTP) has integrated diverse data sources derived from experimental systems with varying biological complexity to understand the mechanisms of toxicity and carcinogenicity induced by the isomeric mixture of tris(chloropropyl) phosphate (TCPP). These diverse data sources include quantitative high-throughput in vitro screening (qHTS) data, short-term toxicogenomic data, and next-generation sequencing (NGS) data of the mouse liver tumors. This appendix summarizes the toxicogenomic results following a 5-day exposure to TCPP.

A 5-day repeat-dose in vivo genomic dose-response study in male rats was performed to characterize TCPP’s biological potency as a means of estimating its toxicological potency in guideline toxicological assessments. In this study, TCPP was shown to increase absolute and relative liver weights at doses ≥1,000 mg TCPP/kg body weight/day (mg/kg/day) with a benchmark dose (BMD) of approximately 589 mg/kg/day.^106^ The most sensitive gene set (gene ontology biological process) BMD of 1 standard deviation (BMD_1SD_) value identified was approximately 26 mg/kg/day in liver. In addition, the relative liver weight change BMD_1SD_ was 253 mg/kg/day. In this appendix, the transcriptomics data generated in the 5-day study were employed to characterize specific mechanisms of toxicity with the goal of providing mechanistic context to the bioassay findings.

## F.2 Material and Methods

A detailed description of the in vivo study, transcriptomic data generation, and quality control can be found in Gwinn et al.^106^ In sum, doses of 0, 18.75, 37.5, 75, 150, 300, 600, 1,000, or 2,000 mg/kg/day were administered by gavage for 5 consecutive days to groups of four male Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) rats and the liver and kidney were collected 24 hours after the last dose. RNA was extracted from the liver and kidney and subjected to high-throughput transcriptomics using the rat TempO-Seq S1500+ platform.^122^

Normalized and log2-transformed S1500+ data from the Gwinn et al.^106^ study were subject to whole-genome extrapolation using the GeniE tool.^123^ GeniE-extrapolated data were used for dose-response analysis as described below. Dose-response analyses of extrapolated gene expression values were performed using BMDExpress 2.3. Data were prefiltered (one data set per chemical) using a Williams trend test (p < 0.05, 1 × 10^4^ dose-level permutations) in combination with a fold-change cutoff of >ǀ2ǀ to remove detector oligos (DOs; two DOs/transcript) that did not demonstrate a response to chemical exposure following BMD analysis. DOs that passed the prefilter were fit to multiple continuous models (linear, exponential 2–5, polynomial of degree 2, and power). An assumption of constant variance across dose groups was made due to the log transformation of the data. To be considered further, model fits had to demonstrate convergent BMD, BMDL (BMD lower 95% confidence limit), and BMDU (BMD upper 95% confidence limit) values. For the models with convergent values, the one with the lowest Akaike information criterion was chosen as the best fit model for each DO. A benchmark response (BMR) of 1 standard deviation (1SD) from the modeled response for the control group for each DO was used to identify a BMD, BMDL, and BMDU. Prior to analysis, DOs were removed that mapped to more than one gene, had a global goodness of fit p value of <0.0001, had a BMD greater than the highest dose level, or had a BMD/BMDL ratio of >20. DOs were then mapped to genes using an individual gene analysis to yield 1 BMD per gene. If more than 1 DO met the above criteria and were mapped to a gene, the average BMD and BMDL of the DO values for that gene were reported as the gene BMD.

Sets of biomarkers were identified by expert review of the literature, signatures were derived from the NTP DrugMatrix Database,^124^ and analysis of the existing data sets was conducted using the Illumina Correlation Engine.^125^ To ensure that all genes in a set reflect an active molecular process (as opposed to loss of activity), they were selected on the basis of their upregulation during a process (i.e., activation of peroxisome proliferator-activated receptor alpha [PPARα]). A list of the genes in each biomarker set are listed in Table F-1. Each biomarker set was evaluated for response in its target tissue and compared with reference chemical responses when appropriate. Importantly, the sets of biomarkers were not intended to diagnose a toxicological effect or mode of action explicitly but instead were meant to provide a weight of evidence, specifically the greater the number of genes responding in a biomarker set (i.e., upregulated with an associated BMD value), the greater confidence that a specific biological or toxicological process was occurring following exposure to the test article. To provide context, results from reference chemicals (DE-71, fenofibrate, and furan) were included in the biomarker set analysis when it was deemed that TCPP elicited a moderate-to-strong response of a biomarker gene set.

Table F-1 Gene Biomarker Sets Evaluated in the Five-day Toxicogenomic Study of Tris(chloropropyl) Phosphate

Biomarker Set | Tissue Specificity | Genes in Biomarker Set
AhR Activation^126-128^ | Liver | Cyp1a2, Cyp1b1, Cyp1a1, Aldh3a1, Fmo1, Cyp2a1, Nqo1, Ahrr
CAR/PXR Activation^127-130^ | Liver | Cyp2b1, Cyp2b2, Ces2c, Abcc3, Aldh1a7, Zdhhc2, Gstp1, Akr7a3, Cyp3a23/3a1, Aldh1a1, Cyp3a2
PPARα Activation^127,128,131,132^ | Liver | Acot1, Fabp3, Acot2, Cpt1b, Hdc, Vnn1, Vldr, Cidea, Pex11a, Lpl, Ehhadh, Chrna1, Cyp4a1, Acaa1a
Nrf2 Activation^126,128,131,133,134^ | Liver | Hmox1, Nqo1, Gsta2, Gsta5, Gstt3, Gstm1, Txnrd1, Gstp1, Ephx1, Prdx1, Gclc, Gclm, Srxn1, Gpx2
Estrogen Receptor Activation^127,128^ | Liver | Rgs3, Ablim3, Orm1, Rbp7, Ctr9, Lifr, Gdf15, Cited4
Inflammation^132,135^ | Any | Lcn2, Cxcl9, A2m, S100a9, Wfdc21, Pla1a, Il1b, Eb13, Marcks, Cd44, Ccl3, Tnfaip3, Serpinb1a, Timp1
Cell Proliferation^132,135^ | Any | Mcm6, Mki67, Ccna2, Cdk1, Ccnb1, Top2a, Pclaf, Aurka, Rrm2, Bub1, Dscc1, Spc25
Genotoxic Hepatocarcinogenicity^128,136-139^ | Liver | Ccng1, Mdm2, Ecn1, Adam8, Aen, Tyms, Phlda3, Bax, Abcb1b, cdkn1a, Nhej, Atp6v1d, Mgmt, Btg2, Pln
Nongenotoxic Hepatocarcinogenicity^136,137,139-144^ | Liver | Acot1, Abcc3, Knstm, Aldh1a1, Abcb1b, Adh7, Gdf15, Akr7a3, Ces2c, Zdhhc2
General Liver Pathology^132,145,146^ | Liver | Pla2g12, Aabcc3, Cyp1a1, Gucy2c, Gadd45b, Ces2c, Wfdc21, Ablim3, Slc4a4, Cidea, Enc1, Zdhhc2, Dact2, Ppl
Overt Liver Toxicity (e.g., cell death, necrosis)^132,147,148^ | Liver | Abcb1b, Abcc3, Btg3, Hmox1, Rbm3, Snx10, Gnai1, Gpx2, Gpnmb, Lcn2, Ccl2, Pvr, Anxa2, Hspb1, Tnfrs12a, Enc1
Acute Kidney Injury^145,146,149-151^ | Kidney | Havcr1, Clu, Timp1, Cp, Anxa2, Gpnmb, Lcn2, Pqlc3, Fgb, Postn

AhR = aryl hydrocarbon receptor; PMID = PubMed identifier; CAR = constitutive androstane receptor; PXR = pregnane X receptor; PPARα = peroxisome proliferator-activated receptor alpha; Nrf2 = nuclear erythroid 2-related factor 2.

## F.3 Results

Five days of oral exposure to TCPP caused an upregulated 122 genes in the liver compared to 727 genes by DE-71 (doses ≤500 mg/kg/day for 5 days), 616 genes by fenofibrate (doses ≤1,000 mg/kg/day for 5 days), and 631 genes by furan (doses ≤16 mg/kg/day for 5 days) in adult male rats (Appendix H). Of the upregulated genes in the liver following exposure to TCPP, the Ar (androgen receptor) had the lowest BMD_1SD_ at 10 mg/kg/day (Figure F-1). Ar “steroid hormone receptors are ligand-activated transcription factors that regulate eukaryotic gene expression and affect cellular proliferation and differentiation in target tissues.”^152-154^ TCPP also upregulated 20 genes in rat kidney following 5 days of repeated exposure. Relative to chemicals that cause kidney toxicity and injury,^106^ the response to TCPP in the kidney was weak. In the kidney, the most sensitive upregulated gene was Ckap2 (cytoskeleton associated protein 2), which had a BMD_1SD_ of 97 mg/kg/day (Figure F-2). Ckap2 “possesses microtubule stabilizing properties,” and “is involved in regulating aneuploidy, cell cycling, and cell death in a p53/TP53-dependent manner.”^155^ Notably, there were 26 upregulated genes with a BMD_1SD_ below 97 mg/kg/day in rat liver indicating that the liver is likely a more sensitive target for TCPP than the kidney when administered by the oral route.

Figure F-1

Dose-response Plots for Ar in Rat Liver and Ckap2 in Rat Kidney Following Exposure to Tris(chloropropyl) Phosphate

Doses are plotted along the horizontal axis and log2 counts per million expression levels are plotted on the vertical axis. A LOTEL is the lowest dose that demonstrates a significant change relative to the control group (t-test, p < 0.05). A) The BMD_1SD_, BMD_L1SD_, and BMD_U1SD_ for Ar in rat liver are 10, 4, and 30 mg/kg/day, respectively. B) The BMD_1SD_, BMD_L1SD_, and BMD_U1SD_ for Ckap2 in rat kidney are 97, 17, and 756 mg/kg/day, respectively. BMD_1SD_ = benchmark dose corresponding to a benchmark response set to 1 standard deviation from the mean; BMD_L1SD_ = benchmark dose lower confidence limit corresponding to a benchmark response set to 1 standard deviation from the mean; BMD_U1SD_ = benchmark dose upper confidence limit corresponding to a benchmark response set to 1 standard deviation from the mean; LOTEL = lowest-observed-transcriptional-effect level; NOTEL = no-observed-transcriptional-effect level.

TCPP upregulated 7 out of 11 CAR and PXR-related biomarker genes in the liver with a low BMD_1SD_ of 250 mg/kg/day. The genes in the biomarker set that were responsive to TCPP included Cyp3a23/3a1, Aldh1a1, Cyp2b1, Ces2c, Cyp2b2, Aldh1a7, and Zdhhc2 (Figure F-2). By comparison, the known CAR and PXR activator, DE-71,^156^ caused upregulation of 10 of the 11 CAR and PXR-related biomarker genes in the liver with a low BMD_1SD_ of 0.3 mg/kg/day. In addition, TCPP also upregulated 8 out of 14 PPARα-related biomarker genes with a low BMD_1SD_ of 105 mg/kg/day. The genes in the biomarker set that were responsive to TCPP included Ehhadh, Hdc, Vnn1, Cyp4a1, Acot2, Acaa1a, Cidea, and Acot1 (Figure F-3). By comparison, the known PPARα activator, fenofibrate,^157^ caused the upregulation of 12 out of 14 PPARα-related biomarker genes in the liver with the lowest, Ehaddh, having a BMD_1SD_ of 0.6 mg/kg/day. There was moderate activity of the nuclear erythroid 2-related factor 2 (Nrf2) biomarker set with 4 out of 14 genes responding to TCPP administration with the lowest sensitive genes, Gsta2 and Gsta5, having a BMD_1SD_ of 576 mg/kg/day. The genes in the biomarker set that were responsive to TCPP included Gsta5, Gsta2, Gstt3, and Gclm. By comparison, the known Nrf2 activator, furan,^158^ caused the upregulation of 6 out of 14 Nrf2 biomarker genes in the liver with the lowest having a BMD_1SD_ of 3.1 mg/kg/day (Figure F-4). These data also demonstrated no activity in key biomarker genes in the liver related to aryl hydrocarbon receptor (AhR), estrogen receptor (ER), genotoxicity, inflammation, and cell proliferation signaling pathways (data not shown).

Figure F-2

Identification of Constitutive Androstane Receptor and Pregnane X Receptor-related Biomarker Genes within the Benchmark Dose Median Accumulation Plot of 123 Upregulated Genes in Rat Liver Following Tris(chloropropyl) Phosphate Exposure for Five Days

Seven out of 11 constitutive androstane receptor (CAR) and pregnane X receptor (PXR)-related biomarker genes were upregulated in response to tris(chloropropyl) phosphate (labeled in the plot and shown in yellow). Of the seven upregulated biomarker genes, Cyp3a23/3a1 had the lowest benchmark dose corresponding to a benchmark response set to 1 standard deviation from the mean (BMD_1SD_) of 250 mg/kg/day. By comparison, the prototype CAR and PXR activator, DE-71, showed upregulation of 10 out of 11 biomarker genes in the liver in a 5-day study. Red squares indicate each individual upregulated gene.

Figure F-3

Identification of Peroxisome Proliferator-activated Receptor Alpha-related Biomarker Genes within the Benchmark Dose Median Accumulation Plot of 123 Upregulated Genes in Rat Liver Following Tris(chloropropyl) Phosphate Exposure for Five Days

Eight out of 14 peroxisome proliferator-activated receptor alpha (PPARα)-related biomarker genes were upregulated in response to tris(chloropropyl) phosphate (labeled in the plot and shown in yellow). Of the eight upregulated biomarker genes, Ehhadh had the lowest benchmark dose corresponding to a benchmark response set to 1 standard deviation from the mean (BMD_1SD_) of 105 mg/kg/day. By comparison, the prototype PPARα activator, fenofibrate, showed upregulation of 12 out of 14 biomarker genes in the liver in a 5-day study. Red squares indicate each individual upregulated gene.

Figure F-4

Identification of Nuclear Erythroid 2-related Factor 2-related Biomarker Genes within the Benchmark Dose Median Accumulation Plot of 123 Upregulated Genes in Rat Liver Following Tris(chloropropyl) Phosphate Exposure for Five Days

Four out of 14 nuclear erythroid 2-related factor 2 (Nrf2) related biomarker genes were upregulated in response to tris(chloropropyl) phosphate (labeled in the plot and shown in yellow). Of the four upregulated biomarker genes, Gsta2 and Gsta5 had the lowest benchmark dose corresponding to a benchmark response set to 1 standard deviation from the mean (BMD_1SD_) of 575 mg/kg/day. By comparison, the prototype Nrf2 activator, furan, showed upregulation of 6 out of 14 biomarker genes in the liver in a 5-day study. Red squares indicate each individual upregulated gene.

The TCPP liver gene expression data were also assessed for several biomarker sets associated with adverse effects. Four out of 14 biomarkers genes (Dact2, Ces2c, Zdhhc2, Cidea) indicative of general liver pathology were responsive to TCPP exposure in the liver with the lowest, Dact2, having a BMD_1SD_ of 133 mg/kg/day (Figure F-5). By comparison, the prototypes DE-71, fenofibrate, and furan (all known to cause pathology in rat liver) caused upregulation of 10, 10, and 6 out of 14 general liver pathology biomarker genes in rat liver in the 5-day study, respectively. This finding suggests some potential for TCPP to cause liver pathology consistent with what is documented in the main body of the report. Notably, only one of the biomarker genes indicative of overt liver toxicity was responsive, denoting that pathological manifestations produced by TCPP are unlikely to induce overt hepatocellular injury at doses as high as 2,000 mg/kg/day (data not shown). Five out of 10 biomarkers genes (Aldh1a1, Ces2c, Zdhhc2, Acot1, Adh7) indicative of nongenotoxic hepatocarcinogenicity were responsive to TCPP exposure in the liver with the lowest, Aldh1a1, having a BMD_1SD_ of 321 mg/kg/day (Figure F-6). By comparison, the prototypes DE-71, fenofibrate, and furan (all known to cause pathology in rat liver) caused upregulation of 7, 5, and 9 out of 10 nongenotoxic hepatocarcinogenicity biomarker genes in rat liver in the 5-day study, respectively. This response of the nongenotoxic hepatocarcinogenicity biomarker genes to TCPP was considered a moderate response and is consistent with the moderate, albeit dose-related, increases in hepatocellular carcinoma in the cancer bioassay. Finally, gene expression data from the kidney showed no upregulation of acute kidney injury biomarker genes.

Figure F-5

Identification of General Liver Pathology-related Biomarker Genes within the Benchmark Dose Median Accumulation Plot of 123 Upregulated Genes in Rat Liver following Tris(chloropropyl) Phosphate Exposure for Five Days

Four out of 14 general liver pathology-related biomarker genes were upregulated in response to tris(chloropropyl) phosphate (labeled in the plot and shown in yellow). Of the four upregulated biomarker genes, Dact2 had the lowest benchmark dose corresponding to a benchmark response set to 1 standard deviation from the mean (BMD_1SD_) of 134 mg/kg/day. By comparison, the prototypes DE-71, fenofibrate, and furan (all known to cause pathology in rat liver) caused upregulation of 10, 10, and 6 out of 14 biomarker genes in the liver in a 5-day study, respectively. Red squares indicate each individual upregulated gene.

Figure F-6

Identification of Nongenotoxic Hepatocarcinogenicity-related Biomarker Genes within the Benchmark Dose Median Accumulation Plot of 123 Upregulated Genes in Rat Liver following Tris(chloropropyl) Phosphate Exposure for Five Days

Five out of 10 nongenotoxic hepatocarcinogenicity-related biomarker genes were upregulated in response to tris(chloropropyl) phosphate (labeled in the plot and shown in yellow). Of the five upregulated biomarker genes, Aldh1a1 had the lowest benchmark dose corresponding to a benchmark response set to 1 standard deviation from the mean (BMD_1SD_) of 321 mg/kg/day. By comparison, the prototypes DE-71, fenofibrate, and furan (all known to cause pathology in rat liver) caused upregulation of 7, 5, and 9 out of 10 biomarker genes in the liver in a 5-day study, respectively. Red squares indicate each individual upregulated gene.

## F.4 Summary

In summary, the mechanistic and toxicological assessment of the transcriptomic data from the 5-day study suggest the liver is more responsive (i.e., overall number of genes responding) and potentially more sensitive to the oral effects of TCPP than is the kidney. The androgen receptor (Ar) in the liver had the lowest benchmark dose of one standard deviation (BMD_1SD_) of 10 mg/kg/day (95% confidence interval: 3.9 to 29.6 mg/kg/day) and the most sensitive endpoint in the kidney was cytoskeleton associated protein 2 (Ckap2) with a BMD_1SD_ of 97 mg/kg/day (95% confidence interval: 16.7 to 756 mg/kg/day), suggesting the liver may be more sensitive than the kidney to TCPP exposure via the oral route. TCPP is a CAR, PXR, and PPARα activator in the rat liver, although to a lesser degree than the reference chemicals, DE-71 and fenofibrate. Other observations included possible Nrf2 activation in rat liver at higher doses.