# Appendix E Bioactivity Screening of Tris(chloropropyl) Phosphate Using Tox21 In Vitro Assay Data

## E.1 Introduction

The National Toxicology Program (NTP) has integrated diverse data sources derived from experimental systems with varying biological complexity to understand the mechanisms of toxicity and carcinogenicity induced by the isomeric mixture of tris(chloropropyl) phosphate (TCPP). These diverse data sources include quantitative high-throughput in vitro screening (qHTS) data, short-term toxicogenomic data, and next-generation sequencing (NGS) data of the mouse liver tumors. This appendix summarizes the activity of TCPP using a qHTS approach.

Countless chemical substances exist in the world, but only a small fraction of these have been adequately assessed for their potential toxicity to humans. The Toxicology in the 21st Century program, or Tox21, is a unique collaboration among several federal agencies established to develop new methods to rapidly test the potential for thousands of substances to adversely affect human health. One method to rapidly generate compound-induced, human-relevant toxicity data is to use the qHTS approach on a large number of substances employing in vitro, human cell-based assays. In Tox21 qHTS, to achieve better confidence in the compound potency data, each substance is tested using 15 concentrations (generally from 5 nM to 92 µM) in three different batches; viability is run in a single batch. Since 2011, approximately 10,000 substances have been screened in more than 70 assays covering mostly human stress response and nuclear receptor pathways. The data provide rich resources from which to query activities of compounds of interest, such as TCPP.

## E.2 Materials and Methods

The data were analyzed as described in a publication by Hsieh et al.^118^ The concentration-response data per substance at each batch (each batch was conducted on different days) was analyzed separately using the Curvep algorithm in the Rcurvep package (v.1.2.0, https://cran.r-project.org/web/packages/Rcurvep/index.html) and activity metrics including the point of departure (POD), maximum response (E_max_), and weighted area under the curve (wAUC) were calculated. The POD is the compound potency at which the elicited response exceeds the noise threshold. The E_max_ is in the percentage scale, relative to the response elicited by the respective assay positive control (PC). In Tox21 assays, the baseline value of E_max_ is set to 0%. A positive or negative E_max_ value indicates an increasing or decreasing effect, respectively, and a higher absolute E_max_ value indicates a stronger effect. The wAUC is a summarized activity value that includes both potency and efficacy information and is weighted by both POD and the testing concentration range, and thus allows for proper across-chemical comparison.^119,120^ The activities from batches were summarized using the median and known artifacts were flagged using the integrative analysis on existing multiple data sources (e.g., readout data in the same screen, counter-screens, and/or external data). Additionally, the substance quality control (QC) information (compound identity, purity, and concentration) was included to remove data with poor QC. The final output from the analysis using the current data sets includes a total of 209 endpoints, each of which has the activity calls at the compound level with summary statistics and warning flags. The activity values at the compound level were summarized (mean) when testing substances had the same activity call (e.g., all active) and acceptable QC. For POD, values were calculated as the mean of log10(M) and then converted back to µM. The activity values resulting from the 209 endpoints were considered directly associated with the annotated target by excluding the current known assay artifacts.

The results were deposited into the NTP database and can be retrieved using the Tox21 Data Application Programming Interface (API) (https://rstudio.niehs.nih.gov/tox21_qhts_api/). The current Tox21 data sets cover 86 protocols and include a total of 209 endpoints. Out of these endpoints for which data were collected, 89 are for detecting nonspecific effects (e.g., cytotoxicity) and 37 are for identifying autofluorescent chemical structures in various conditions. The remaining 83 endpoints are for detecting specific effects such as covering activation/inhibition of nuclear receptor pathways, activation of stress response pathways, and inhibition of cytochrome P450 (CYP).

## E.3 Results

### E.3.1 Activity of Tris(chloropropyl) Phosphate in Tox21 Assays

In the Tox21 library, two independent substances (Tox21_202982 and Tox21_303533) were identified as TCPP and were tested in the Tox21 assays. Both substances had acceptable QC (https://tripod.nih.gov/tox/samples) and their data were first used to generate activity results at the substance level then at the compound level. The activity results at the compound level are discussed throughout the report.

TCPP showed activities in 10 endpoints from the Tox21 qHTS assessment. Seven of 10 endpoints were related to xenobiotic homeostasis, particularly activation of the pregnane X receptor (PXR) signaling pathway and the constitutive androstane receptor (CAR) pathway, and the inhibition of CYP 1A2, 2C19, 2C9, 3A4, and 2D6. TCPP induced cytotoxicity in two separate assays and was associated with inhibition of the progesterone receptor (PR) signaling pathway involved in sex hormone homeostasis. The POD and E_max_ of the activities in these 10 endpoints are plotted in Figure E-1. The underlying activity data in Figure E-1 are provided in Table E-1, including the experimental protocol information deposited in PubChem (https://pubchem.ncbi.nlm.nih.gov/). For the 10 endpoints that TCPP showed activity, the concentration-response curves associated with each endpoint, in addition to the activity results at the testing substance level, are provided in Figure E-1 to Figure E-12. The activation of the PXR pathway was also supported by other orthogonal Toxicity Forecasting (ToxCast) assays including Attagene and Novascreen^2^ (available at https://comptox.epa.gov/dashboard).

Table E-1 Tris(chloropropyl) Phosphate Activity Data in Tox21 Quantitative High-throughput Screening Assays

Endpoint | Target | Target Group | Lowest Tested Concentration (µM) | Highest Tested Concentration (µM) | POD (µM) | E_max_ (%) | # of Activity Calls of Substances | # of Activity Calls without Artifact Flags | PubChem AID
tox21-car-agonist-p1_car-agonist_1^a^ | car-agonist | xenobiotic homeostasis | 0.001121 | 92.34215 | 44.55 | 24.58 | 2 | 2 | 1224892
tox21-p450-1a2-p1_1a2-inhibitor_1^b^ | 1a2-inhibitor | xenobiotic homeostasis | 0.001398 | 115.1596 | 2.63 | −84.72 | 2 | 2 | 1671199
tox21-p450-2c9-p1_2c9-inhibitor_1^c^ | 2c9-inhibitor | xenobiotic homeostasis | 0.001398 | 115.1596 | 37.88 | −56.40 | 2 | 2 | 1671198
tox21-p450-2c19-p1_2c19-inhibitor_1^d^ | 2c19-inhibitor | xenobiotic homeostasis | 0.001398 | 115.1596 | 14.36 | −122.41 | 2 | 2 | 1671197
tox21-p450-2d6-p1_2d6-inhibitor_1^e^ | 2d6-inhibitor | xenobiotic homeostasis | 0.001398 | 115.1596 | 65.80 | −25.21 | 2 | 2 | 1671196
tox21-p450-3a4-p1_3a4-inhibitor_1^f^ | 3a4-inhibitor | xenobiotic homeostasis | 0.001474 | 115.1596 | 92.81 | −32.72 | 2 | 2 | 1671201
tox21-pr-bla-antagonist-p1_pr-antagonist_1^g^ | pr-antagonist | sex hormone homeostasis | 0.001121 | 87.55884 | 36.94 | −46.43 | 2 | 1 | 1347031
tox21-pxr-p1_pxr-agonist_1^h^ | pxr-agonist | xenobiotic homeostasis | 0.001121 | 92.34215 | 20.07 | 38.66 | 2 | 2 | 1347033
tox21-rt-viability-hek293-p1_viability@glo_40h_1^i^ | viability@glo_40h | cytotoxicity | 9.32E-04 | 76.7715 | 65.83 | −18.32 | 2 | 2 | 1224874
tox21-rt-viability-hek293-p1_viability@glo_1^j^ | viability@glo | cytotoxicity | 9.32E-04 | 76.7715 | 31.75 | −23.99 | 2 | 2 | NA

POD = point of departure; E_max_ = maximum response; AID = assay identifier; NA = not applicable.

^a^ qHTS assay in a double-stable (hCAR and CYP2B6-2.2kb) transfected cell line derived from HepG2 cells to identify small molecule agonists of the constitutive androstane receptor (CAR) signaling pathway.

^b^ Luciferase reporter qHTS assay for small molecule antagonists of Cytochrome P450 Family 1 Subfamily A Member 2 (CYP1A2).

^c^ Luciferase reporter qHTS assay for small molecule antagonists of CYP2C9.

^d^ Luciferase reporter qHTS assay for small molecule antagonists of CYP2C19.

^e^ Luciferase reporter qHTS assay for small molecule antagonists of CYP2D6.

^f^ Luciferase reporter qHTS assay for small molecule antagonists of CYP3A4.

^g^ qHTS assay in PR-UAS-bla HEK293T cells to identify small molecule antagonists of the progesterone receptor (PR) signaling pathway.

^h^ qHTS assay in PXR-Luc HepG2 cells to identify small molecule agonists of the human pregnane X receptor (PXR).

^i^ Quantitative high-throughput sequencing (qHTS) RealTime-Glo MT Cell Viability Assay in HEK293 cells—40 hour is a luciferase-based measure of cell viability based on luminescence at 40 hours.

^j^ qHTS RealTime-Glo MT Cell Viability Assay in HEK293 cells is a luciferase-based measure of cell viability based on luminescence over time; timepoints assayed were 0, 8, 16, 24, 32, and 40 hours.

Figure E-1

Tris(chloropropyl) Phosphate Activity in Tox21 Quantitative High-throughput Screening Assays

The red dashed line represents 0%; data points above this line represent activation while points below represent inhibition. 2d6 = cytochrome P450 (CYP) 2D6; 3a4 = CYP 3A4; 2c9 = CYP 2C9; 1a2 = CYP 1A2; 2c19 = CYP 2C19; CAR = constitutive androstane receptor; glo = RealTime-Glo MT Cell Viability Assay over time; glo_40h = RealTime-Glo MT Cell Viability Assay at 40 hours of exposure; PC = positive control; PR = progesterone receptor; PXR = pregnane X receptor; POD = point of departure.

Figure E-2

Concentration-response Curves of Tris(chloropropyl) Phosphate Agonism of the Constitutive Androstane Receptor in HepG2 Cells

Results from 15 tested concentrations in three Tox21 batches for tox21-car-agonist-p1_car-agonist_1 are shown above for A) active agonism of the constitutive androstane receptor (CAR) by tris(chloropropyl) phosphate (TCPP; Tox21_202982) with no artifact flags, a point of departure (POD) of 54.66 µm, and a maximum response (E_max_) of 27%; and B) active agonism of CAR by TCPP (Tox21_303533) with no artifact flags, a POD of 36.29 µm, and an E_max_ of 22.17%. The compound level POD and E_max_ are 44.55 µm and 24.58%, respectively, with an overall activity call of active. A dose-response line of best fit is shown for each batch.

Figure E-3

Concentration-response Curves of Tris(chloropropyl) Phosphate Inhibition of Cytochrome P450 1a2

Results from 15 tested concentrations in three Tox21 batches for tox21-p450-1a2-p1_1a2-inhibitor_1 are shown above for A) active inhibition of cytochrome P450 (CYP) 1a2 by tris(chloropropyl) phosphate (TCPP; Tox21_202982) with no artifact flags, a point of departure (POD) of 1.89 µm, and a maximum response (E_max_) of −84.78%; and B) active inhibition of CYP1a2 by TCPP (Tox21_303533) with no artifact flags, a POD of 3.66 µm, and an E_max_ of −84.65%. The compound level POD and E_max_ are 2.63 µm and −84.72%, respectively, with an overall activity call of active. A dose-response line of best fit is shown for each batch.

Figure E-4

Concentration-response Curves of Tris(chloropropyl) Phosphate Inhibition of Cytochrome P450 2c19

Results from 15 tested concentrations in three Tox21 batches for tox21-p450-2c19-p1_2c19-inhibitor_1 are shown above for A) active inhibition of cytochrome P450 (CYP) 2c19 by tris(chloropropyl) phosphate (TCPP; Tox21_202982) with no artifact flags, a point of departure (POD) of 15.53 µm, and a maximum response (E_max_) of −130.64%; and B) active inhibition of CYP2c19 by TCPP (Tox21_303533) with no artifact flags, a POD of 13.27 µm, and an E_max_ of −114.17%. The compound level POD and E_max_ are 14.36 µm and −122.41%, respectively, with an overall activity call of active. A dose-response line of best fit is shown for each batch.

Figure E-5

Concentration-response Curves of Tris(chloropropyl) Phosphate Inhibition of Cytochrome P450 2c9

Results from 15 tested concentrations in three Tox21 batches for tox21-p450-2c9-p1_2c9-inhibitor_1 are shown above for A) active inhibition of cytochrome P450 (CYP) 2c9 by tris(chloropropyl) phosphate (TCPP; Tox21_202982) with no artifact flags, a point of departure (POD) of 36.12 µm, and a maximum response (E_max_) of −58.06%; and B) active inhibition of CYP2c9 by TCPP (Tox21_303533) with no artifact flags, a POD of 39.72 µm, and an E_max_ of −54.74%. The compound level POD and E_max_ are 37.88 µm and −56.4%, respectively, with an overall activity call of active. A dose-response line of best fit is shown for each batch.

Figure E-6

Concentration-response Curves of Tris(chloropropyl) Phosphate Inhibition of Cytochrome P450 2d6

Results from 15 tested concentrations in three Tox21 batches for tox21-p450-2d6-p1_2d6-inhibitor_1 are shown above for A) active inhibition of cytochrome P450 (CYP) 2d6 by tris(chloropropyl) phosphate (TCPP; Tox21_202982) with no artifact flags, a point of departure (POD) of 104.45 µm, and a maximum response (E_max_) of −22.76%; and B) active inhibition of CYP2d6 by TCPP (Tox21_303533) with no artifact flags, a POD of 41.45 µm, and an E_max_ of −27.65%. The compound level POD and E_max_ are 65.80 µm and −25.21%, respectively, with an overall activity call of active. A dose-response line of best fit is shown for each batch.

Figure E-7

Concentration-response Curves of Tris(chloropropyl) Phosphate Inhibition of Cytochrome P450 3a4

Results from 15 tested concentrations in three Tox21 batches for tox21-p450-3a4-p1_3a4-inhibitor_1 are shown above for A) active inhibition of cytochrome P450 (CYP) 3a4 by tris(chloropropyl) phosphate (TCPP; Tox21_202982) with no artifact flags, a point of departure (POD) of 93.28 µm, and a maximum response (E_max_) of −33.86%; and B) active inhibition of CYP3a4 by TCPP (Tox21_303533) with no artifact flags, a POD of 92.32 µm, and an E_max_ of −31.59%. The compound level POD and E_max_ are 92.81 µm and −32.72%, respectively, with an overall activity call of active. A dose-response line of best fit is shown for each batch.

Figure E-8

Concentration-response Curves of Tris(chloropropyl) Phosphate Agonism of the Progesterone Receptor in HEK293 Cells

Results from 15 tested concentrations in three Tox21 batches for tox21-pr-bla-antagonist-p1_pr-antagonist_1 are shown above for A) inconclusive antagonism of the progesterone receptor (PR) by tris(chloropropyl) phosphate (TCPP; Tox21_202982) with an artifact flag of potency_overlap_with_counterscreen, a point of departure (POD) of 39.14 µm, and a maximum response (E_max_) of −60.02%; and B) active antagonism of PR by TCPP (Tox21_303533) with no artifact flags, a POD of 36.94 µm, and an E_max_ of −46.43%. The compound level POD and E_max_ are 36.94 µm and −46.94%, respectively, with an overall activity call of active. A dose-response line of best fit is shown for each batch. Ch1 = channel 1, background readout; Ch2 = channel 2, reporter gene readout; Ratio = the ratio of Ch2:Ch1.

Figure E-9

Concentration-response Curves of Tris(chloropropyl) Phosphate Agonism of the Pregnane X Receptor in HepG2 Cells

Results from 15 tested concentrations in three Tox21 batches for tox21-pxr-p1_pxr-agonist_1 are shown above for A) active agonism of the pregnane X receptor (PXR) by tris(chloropropyl) phosphate (TCPP; Tox21_202982) with no artifact flags, a point of departure (POD) of 31.02 µm, and a maximum response (E_max_) of 37.08%; and B) active agonism of PXR by TCPP (Tox21_303533) with no artifact flags, a POD of 12.99 µm, and an E_max_ of 40.24%. The compound level POD and E_max_ are 20.07 µm and 38.66%, respectively, with an overall activity call of active. A dose-response line of best fit is shown for each batch.

Figure E-10

Concentration-response Curves of Tris(chloropropyl) Phosphate on Viability in HEK293 Cells at 0, 8, 16, 24, 32, and 40 Hours

Results from 15 tested concentrations in one Tox21 batch for tox21-rt-viability-hek293-p1_viability@glo_1 are shown above for A) decreased viability by tris(chloropropyl) phosphate (TCPP; Tox21_202982) with no artifact flags, a point of departure (POD) of 14.06 µm, and a maximum response (E_max_) of −32.68%; and B) decreased viability by TCPP (Tox21_303533) with no artifact flags, a POD of 71.66 µm, and an E_max_ of −15.30%. The compound level POD and E_max_ are 31.75 µm and −23.99%, respectively, with an overall activity call of active. A dose-response line of best fit is shown for each batch. Glo_0h_n = cell viability readout at 0 hours; Glo_16h_n = cell viability readout at 16 hours; Glo_24h_n = cell viability readout at 24 hours; Glo_32h_n = cell viability readout at 32 hours; Glo_40h_n = cell viability readout at 40 hours; Glo_8h_n = cell viability readout at 8 hours.

Figure E-11

Concentration-response Curves of Tris(chloropropyl) Phosphate on Viability in HEK293 Cells at 40 Hours

Results from 15 tested concentrations in one Tox21 batch for tox21-rt-viability-hek293-p1_viability@glo_40h_1 are shown above for A) decreased viability by tris(chloropropyl) phosphate (TCPP; Tox21_202982) with no artifact flags, a point of departure (POD) of 60.46 µm, and a maximum response (E_max_) of −21.33%; and B) decreased viability by TCPP (Tox21_303533) with no artifact flags, a POD of 71.66 µm, and an E_max_ of −15.3%. The compound level POD and E_max_ are 65.83 µm and −18.32%, respectively, with an overall activity call of active. A dose-response line of best fit is shown for each batch.

### E.3.2 Activity of Tris(chloropropyl) Phosphate Compared with Reference Chemicals

Among the activities that TCPP displayed in Tox21 qHTS assays were clear effects on PXR and CAR activation (Figure E-1, Figure E-2, Figure E-9). The degree of the effect was compared with reference chemicals that were also tested in the Tox21 assays. The reference chemicals for activation of PXR and CAR were selected from Judson et al.^121^ The reference chemicals selected included those with the highest number of available supporting reports and were also active in the related Tox21 assays. For PXR activation, rifampicin was selected (support # = 13); for CAR activation, bisphenol A (support # = 3) and methoxychlor (support # = 3) were selected.

The effect of PXR or CAR activation by the reference chemicals was compared with that of TCPP in relation to all the other active chemicals in the related Tox21 screens (Figure E-12) using the wAUC activity metric. In Figure E-12A, the effect of rifampicin is within the top 5% of active chemicals to activate PXR, and TCPP is within the top 50%. In Figure E-12B, the effects of methoxychlor and bisphenol A are within the top 0.2% and 4%, respectively, of active chemicals to activate CAR, and TCPP is within the top 66%.

Figure E-12

Comparison of Tris(chloropropyl) Phosphate Potency to Assay Reference Chemicals in Tox21

A) Pregnane X receptor (PXR) and B) constitutive androstane receptor (CAR) activation in Tox21 assays (gray dots) plotted based on weighted area under the curve (wAUC) value. Each individual gray dot represents all active chemicals in the related Tox21 screens, organized by wAUC values. Tris(chloropropyl) phosphate (TCPP) activity versus rifampicin activity (PXR reference chemical) is highlighted in panel A (red dots). TCPP activity versus bisphenol A and methoxychlor activity (CAR reference chemicals) is highlighted in panel B (red dots).

## E.4 Summary

In summary, the in vitro data suggest that TCPP activates PXR and CAR, although to a lesser degree than do the reference chemicals rifampicin for PXR and bisphenol A and methoxychlor for CAR.