# Appendix D Genetic Toxicology

## D.1 Evaluation Protocol

The National Toxicology Program (NTP) considers biological as well as statistical factors to determine an overall assay result. For an individual assay, the statistical procedures for data analysis are described in the following protocols. There have been instances, however, in which multiple samples of a chemical were tested in the same assay, and different results were obtained among these samples and/or among laboratories. In such cases, all the data are critically evaluated with attention given to possible protocol variations in determining the weight of evidence for an overall conclusion of chemical activity in an assay. For in vitro assays conducted with and without exogenous metabolic activation, results obtained in the absence of activation are analyzed separately from results obtained in the presence of activation. The summary table in the abstract of this Technical Report presents NTP’s scientific judgment regarding the overall evidence for activity of the chemical in an assay.

## D.2 Bacterial Mutagenicity

### D.2.1 Bacterial Mutagenicity Test Protocol

Testing procedures were modified from those originally reported by Zeiger et al.^90^ Two independent studies were conducted. In the first study, coded samples of the isomeric mixture of tris(chloropropyl) phosphate (TCPP) were incubated with the Salmonella typhimurium (TA97, TA98, TA100, TA1535, TA1537) tester strains either in buffer or S9 mix (metabolic activation enzymes and cofactors from Aroclor 1254-induced male Sprague Dawley rat or Syrian hamster liver) for 20 minutes at 37°C. In the second study, blinded samples of TCPP (the same chemical lot that was used in the 2-year bioassays) were incubated with S. typhimurium strains TA98 and TA100 or Escherichia coli WP2 uvrA (pKM101) either in buffer or S9 mix (metabolic activation enzymes and cofactors from phenobarbital/benzoflavone-induced male Sprague Dawley rat liver) for 20 minutes at 37°C. In both studies, top agar supplemented with L-histidine (or tryptophan for the E. coli strain) and d-biotin was added, and the contents of the tubes were mixed and poured onto the surfaces of minimal glucose agar plates. Histidine- or tryptophan-independent mutant colonies arising on these plates were counted after incubation for 2 days at 37°C.

Each trial consisted of triplicate plates of concurrent positive and negative controls and of at least five doses of TCPP. Dose-limiting toxicity was observed in all S. typhimurium strains in the first study. In the second study, dose-limiting toxicity was observed in both S. typhimurium strains but not in the E. coli strain. All trials were repeated.

In this assay, a positive response is defined as a reproducible, dose-related increase in histidine-independent (revertant) colonies in any one strain/activation combination. An equivocal response is defined as an increase in revertants that is not dose-related, is not reproducible, or is not of sufficient magnitude to support a determination of mutagenicity. A negative response is obtained when no increase in revertant colonies is observed after chemical treatment. No minimum percentage or fold increase is required for a chemical to be judged positive or weakly positive, although positive calls are typically reserved for increases in mutant colonies that are at least twofold over background.

### D.2.2 Results

TCPP did not induce mutations, with or without the addition of exogenous metabolic activation enzymes supplied by induced rat or hamster liver S9 in various concentrations, in any of several strains of bacteria (S. typhimurium and E. coli), in two bacterial mutagenicity studies (Table D-1, Table D-2). In Study 1 (study number 815918), the highest dose tested was limited by toxicity to 1,000 µg/plate; in Study 2 (study number G20263C), although toxicity was again observed in some trials at 1,000 µg/plate, higher doses (ranging up to 6,000 µg/plate) could be tested, particularly in the E. coli strain.

Table D-1 Mutagenicity of Tris(chloropropyl) Phosphate in Bacterial Tester Strains (Study 1)^a^

Strain | Concentration (μg/plate) | Without S9 | Without S9 | With 5% Rat S9 | With 10% Rat S9 | With 10% Rat S9 | With 30% Rat S9 | With 30% Rat S9 | With 10% Hamster S9 | With 10% Hamster S9 | With 30% Hamster S9
TA97
| 0 | 79 ± 4.1 | 97 ± 0.9 | – | 110 ± 3.7 | – | 170 ± 15.5 | – | 106 ± 6.8 | – | 91 ± 11.6
| 3.3 | – | 89 ± 4.9 | – | – | – | – | – | – | – | –
| 10 | 68 ± 6.2 | 76 ± 9.5 | – | 121 ± 3.2 | – | 167 ± 7.8 | – | 116 ± 3.5 | – | 92 ± 2.1
| 33 | 71 ± 1.9 | 91 ± 5.8 | – | 118 ± 11.1 | – | 170 ± 5.0 | – | 92 ± 2.9 | – | 94 ± 3.8
| 100 | 76 ± 4.5 | 90 ± 4.3 | – | 114 ± 2.8 | – | 172 ± 6.1 | – | 117 ± 7.2 | – | 85 ± 1.5
| 333 | 70 ± 8.4 | 91 ± 10.1 | – | 102 ± 3.6 | – | 159 ± 12.8 | – | 116 ± 2.0 | – | 99 ± 13.6
| 666 | – | – | – | 86 ± 3.7^b^ | – | – | – | 92 ± 4.1^b^ | – | –
| 667 | Toxic | – | – | – | – | – | – | – | – | –
| 1,000 | – | – | – | – | – | 62 ± 7.0^b^ | – | – | – | Toxic
Trial Summary | | Negative | Negative | – | Negative | – | Negative | – | Negative | – | Negative
Positive Control^c^ | | 434 ± 3.2 | 246 ± 28.7 | – | 1,137 ± 7.8 | – | 556 ± 32.5 | – | 804 ± 22.1 | – | 474 ± 24.0
TA98
| 0 | 16 ± 0.9 | 14 ± 1.5 | – | 30 ± 6.1 | – | 29 ± 3.8 | – | 29 ± 2.3 | – | 30 ± 3.5
| 3.3 | – | 16 ± 1.5 | – | – | – | – | – | – | – | –
| 10 | 17 ± 1.5 | 13 ± 3.8 | – | 33 ± 3.7 | – | 36 ± 1.8 | – | 28 ± 2.1 | – | 37 ± 3.8
| 33 | 19 ± 0.9 | 15 ± 1.2 | – | 21 ± 3.5 | – | 29 ± 2.5 | – | 23 ± 3.5 | – | 36 ± 1.5
| 100 | 17 ± 3.7 | 13 ± 2.3 | – | 22 ± 1.5 | – | 28 ± 0.9 | – | 23 ± 3.6 | – | 29 ± 3.9
| 333 | 18 ± 1.5 | 18 ± 0.6 | – | 23 ± 0.3 | – | 23 ± 1.2 | – | 26 ± 2.5 | – | 37 ± 3.9
| 666 | – | – | – | 26 ± 3.1^b^ | – | – | – | 28 ± 0.9 | – | –
| 667 | 18 ± 1.0 | – | – | – | – | – | – | – | – | –
| 1,000 | – | – | – | – | – | 27 ± 1.2^b^ | – | – | – | 24 ± 4.9^b^
Trial Summary | | Negative | Negative | – | Negative | – | Negative | – | Negative | – | Negative
Positive Control | | 154 ± 4.4 | 527 ± 38.2 | – | 284 ± 52.8 | – | 84 ± 2.0 | – | 237 ± 3.2 | – | 88 ± 5.7
TA100
| 0 | 152 ± 6.9 | 162 ± 4.7 | – | 135 ± 7.0 | – | 128 ± 2.9 | – | 127 ± 3.2 | 94 ± 3.5 | 142 ± 6.1
| 3.3 | – | 118 ± 7.6 | – | – | – | – | – | – | – | –
| 10 | 157 ± 2.4 | 126 ± 29.0 | – | 138 ± 7.2 | – | 131 ± 6.4 | – | 126 ± 9.4 | 91 ± 3.3 | 157 ± 20.5
| 33 | 144 ± 6.4 | 156 ± 2.5 | – | 139 ± 7.2 | – | 133 ± 5.0 | – | 157 ± 2.9 | 83 ± 4.1 | 130 ± 2.3
| 100 | 145 ± 4.9 | 127 ± 2.8 | – | 128 ± 8.6 | – | 135 ± 6.1 | – | 176 ± 8.7 | 105 ± 2.1 | 113 ± 12.0
| 333 | 145 ± 2.6 | 126 ± 1.0 | – | 119 ± 6.6 | – | 148 ± 0.7 | – | 186 ± 9.2 | 131 ± 7.1 | 162 ± 8.6
| 666 | – | – | – | 84 ± 4.9^b^ | – | – | – | 132 ± 4.5^b^ | 100 ± 4.0 | –
| 667 | 128 ± 2.6^b^ | – | – | – | – | – | – | – | – | –
| 1,000 | – | – | – | – | – | 111 ± 23.3^b^ | – | – | – | 112 ± 9.5^b^
Trial Summary | | Negative | Negative | – | Negative | – | Negative | – | Equivocal | Equivocal | Negative
Positive Control | | 468 ± 13.8 | 351 ± 91.9 | – | 801 ± 92.3 | – | 398 ± 5.0 | – | 719 ± 41.6 | 541 ± 7.2 | 494 ± 5.3
TA1535
| 0 | 35 ± 0.9 | 24 ± 1.8 | 12 ± 0.3 | 12 ± 1.5 | 13 ± 3.0 | 15 ± 3.6 | 11 ± 3.2 | 13 ± 0.9 | 10 ± 1.2 | 9 ± 2.3
| 3.3 | – | 20 ± 4.0 | – | – | – | – | – | – | – | –
| 10 | 36 ± 1.7 | 24 ± 3.0 | – | – | 12 ± 2.3 | 16 ± 0.3 | – | 10 ± 3.8 | 12 ± 2.7 | 10 ± 2.6
| 33 | 38 ± 3.4 | 25 ± 1.8 | 11 ± 2.3 | 14 ± 1.9 | 8 ± 0.7 | 15 ± 1.7 | 13 ± 2.2 | 12 ± 0.6 | 8 ± 1.9 | 17 ± 2.6
| 100 | 34 ± 5.3 | 26 ± 1.5 | 11 ± 0.3 | 10 ± 2.0 | 10 ± 1.2 | 17 ± 3.1 | 9 ± 1.0 | 10 ± 1.8 | 11 ± 1.9 | 12 ± 2.3
| 333 | 37 ± 6.0 | 23 ± 1.7 | 7 ± 0.6 | 7 ± 1.0 | 11 ± 2.3 | 28 ± 3.6 | 12 ± 1.0 | 20 ± 1.5 | 18 ± 4.8 | 10 ± 1.9
| 666 | – | – | – | – | 10 ± 1.5^b^ | – | – | 23 ± 0.3^b^ | 16 ± 4.3^b^ | –
| 667 | 11 ± 10.5^b^ | – | 11 ± 1.9^b^ | 8 ± 1.3 | – | – | 9 ± 1.0 | – | – | –
| 1,000 | – | – | 6 ± 1.5^b^ | 5 ± 0.3^b^ | – | 24 ± 3.2^b^ | 7 ± 2.0^b^ | – | – | 9 ± 3.2^b^
Trial Summary | | Negative | Negative | Negative | Negative | Negative | Equivocal | Negative | Equivocal | Negative | Negative
Positive Control | | 210 ± 0.6 | 60 ± 5.1 | 129 ± 7.1 | 155 ± 2.5 | 113 ± 4.2 | 134 ± 8.0 | 143 ± 6.7 | 281 ± 4.9 | 50 ± 2.8 | 48 ± 5.5
TA1537
| 0 | 4 ± 0.3 | – | – | – | – | 6 ± 0.0 | – | – | – | 8 ± 1.5
| 10 | 7 ± 0.6 | – | – | – | – | 9 ± 3.2 | – | – | – | 6 ± 1.5
| 33 | 6 ± 1.7 | – | – | – | – | 7 ± 1.2 | – | – | – | 5 ± 2.6
| 100 | 6 ± 1.9 | – | – | – | – | 8 ± 1.9 | – | – | – | 8 ± 2.3
| 333 | 5 ± 1.9 | – | – | – | – | 7 ± 1.5 | – | – | – | 5 ± 0.9
| 667 | 6 ± 0.9^b^ | – | – | – | – | – | – | – | – | –
| 1,000 | – | – | – | – | – | 5 ± 1.2^b^ | – | – | – | 5 ± 0.3^b^
Trial Summary | | Negative | – | – | – | – | Negative | – | – | – | Negative
Positive Control | | 258 ± 7.9 | – | – | – | – | 76 ± 4.7 | – | – | – | 55 ± 1.8

^a^ Studies performed at BioReliance Corporation. Data are presented as revertants/plate (mean ± standard error) from three plates; 0 μg/plate served as the solvent control (dimethyl sulfoxide).

^b^ Slight toxicity.

^c^ The positive controls in the absence of metabolic activation were sodium azide (TA100, TA1535), 9-aminoacridine (TA97, TA1537), and 4-nitro-o-phenylenediamine (TA98). The positive control for metabolic activation with all strains was 2-aminoanthracene.

Table D-2 Mutagenicity of Tris(chloropropyl) Phosphate in Bacterial Tester Strains (Study 2)^a^

Strain | Concentration (μg/plate) | Without S9 | Without S9 | With 10% Rat S9 | With 10% Rat S9
TA98
| 0 | 18 ± 2.1 | 15 ± 3.1 | 23 ± 2.3 | 18 ± 2.4
| 40 | – | 10 ± 2.1 | – | –
| 80 | – | 11 ± 2.3 | – | 24 ± 4.6
| 100 | 15 ± 3.1 | – | 16 ± 0.9 | –
| 200 | – | 15 ± 3.2 | – | 19 ± 2.3
| 250 | 14 ± 2.6 | – | 15 ± 3.8 | –
| 500 | 20 ± 1.5 | 18 ± 4.0 | 24 ± 0.9 | 13 ± 2.0
| 750 | – | 19 ± 2.0 | – | –
| 1,000 | 18 ± 3.5 | 13 ± 1.7 | 18 ± 0.6 | 15 ± 3.5
| 2,000 | Toxic | Toxic | – | –
| 3,000 | Toxic | – | 15 ± 4.0 | 5 ± 0.9
| 6,000 | – | – | 16 ± 8.2 | 6 ± 3.7
Trial Summary | | Negative | Negative | Negative | Negative
Positive Control^b^ | | 697 ± 9.5 | 548 ± 7.0 | 1,659 ± 73.5 | 1,089 ± 22.2
TA100
| 0 | 88 ± 1.5 | 75 ± 4.6 | 81 ± 4.2 | 85 ± 3.2
| 40 | – | 73 ± 4.1 | – | –
| 80 | – | 67 ± 5.8 | – | –
| 100 | 83 ± 3.8 | – | 89 ± 3.5 | –
| 200 | – | 85 ± 1.3 | – | 83 ± 4.3
| 250 | 80 ± 11.9 | – | 94 ± 4.6 | –
| 300 | – | – | – | 78 ± 2.6
| 500 | 81 ± 6.2 | 79 ± 2.6 | 83 ± 5.0 | –
| 750 | – | 58 ± 4.2 | – | –
| 1,000 | Toxic | Toxic | 67 ± 7.6 | 80 ± 5.0
| 2,000 | Toxic | Toxic | – | Toxic
| 3,000 | Toxic | – | Toxic | Toxic
| 6,000 | – | – | Toxic | Toxic
Trial Summary | | Negative | Negative | Negative | Negative
Positive Control | | 654 ± 20.9 | 541 ± 10.7 | 791 ± 24.9 | 422 ± 16.1
Escherichia coli WP2 uvrA (pKM101)
| 0 | 114 ± 1.9 | 99 ± 8.2 | 149 ± 4.6 | 139 ± 5.6
| 100 | 123 ± 10.7 | 108 ± 6.7 | 155 ± 5.2 | 145 ± 12.7
| 250 | 110 ± 3.3 | 100 ± 1.9 | 150 ± 4.3 | 157 ± 3.2
| 500 | 104 ± 12.7 | 95 ± 5.9 | 150 ± 6.2 | 133 ± 5.8
| 1,000 | 100 ± 3.7 | 96 ± 4.9 | 168 ± 1.9 | 119 ± 9.3
| 3,000 | 86 ± 7.5 | 74 ± 8.2 | 111 ± 5.8 | 94 ± 4.8
| 6,000 | 73 ± 7.6 | 88 ± 2.9 | 111 ± 2.5 | 92 ± 3.5
Trial Summary | | Negative | Negative | Negative | Negative
Positive Control | | 2,291 ± 125.2 | 2,313 ± 73.3 | 978 ± 16.1 | 895 ± 39.4

^a^ Studies performed at Integrated Laboratory Systems, LLC. Data are presented as revertants/plate (mean ± standard error) from three plates; 0 μg/plate served as the solvent control (dimethyl sulfoxide).

^b^ The positive controls in the absence of metabolic activation were sodium azide (TA100), 2-nitrofluorene (TA98), and 4-nitroquinoline-N-oxide (E. coli). The positive controls for metabolic activation were 2-aminoanthracene (TA98, E. coli) and benzo[a]pyrene (TA100).

## D.3 Micronucleus Assay

### D.3.1 Peripheral Blood Micronucleus Test Protocol

At termination of the 3-month toxicity studies of TCPP, blood samples (approximately 200 μL) were collected from male and female rats and mice, placed in ethylenediaminetetraacetic acid (EDTA)-coated tubes, and shipped overnight to the testing laboratory. Upon arrival, blood samples were fixed in ultracold methanol using a MicroFlowPLUS Kit (Litron Laboratories, Rochester, NY) according to the manufacturer’s instructions. Fixed samples were stored in a −80°C freezer until analysis. Thawed blood samples were analyzed for frequency of micronucleated immature erythrocytes (i.e., reticulocytes or polychromatic erythrocytes [PCEs]) and mature erythrocytes (i.e., normochromatic erythrocytes [NCEs]) using a flow cytometer^115^; both the mature and the immature erythrocyte populations can be analyzed separately by employing special cell surface markers to differentiate the two cell types. Because the very young reticulocyte subpopulation (CD71+ cells) can be targeted using this technique, rat blood samples can be analyzed for damage that occurred in the bone marrow within the past 24–48 hours, before the rat spleen appreciably alters the percentage of PCEs in circulation.^116^ In mice, both the immature and mature erythrocyte populations can be evaluated for micronucleus frequency because the mouse spleen does not sequester and eliminate damaged erythrocytes. Damaged erythrocytes achieve steady state in the peripheral blood of mice after 4 weeks of continuous exposure. Approximately 20,000 PCEs and 1 × 10^6^ NCEs were analyzed per animal for frequency of micronucleated cells, and the percentage of immature erythrocytes (% PCE) was calculated as a measure of bone marrow toxicity resulting from chemical exposure.

Prior experience with the large number of cells scored using flow cytometric scoring techniques^117^ suggests it is reasonable to assume that the proportion of micronucleated reticulocytes is approximately normally distributed. The statistical tests selected for trend and for pairwise comparisons with the control group depend on whether the variances among the groups are equal. The Levene test at α = 0.05 is used to test for equal variances. In the case of equal variances, linear regression is used to test for a linear trend with exposure concentration and the Williams test is used to test for pairwise differences between each exposed group and the control group. In the case of unequal variances, the Jonckheere test is used to test for linear trend and the Dunn test is used for pairwise comparisons of each exposed group with the control group. To correct for multiple pairwise comparisons, the p value for each comparison with the control group is multiplied by the number of comparisons made. In the event that this product is >1.00, it is replaced with 1.00. Trend tests and pairwise comparisons with the control group are considered statistically significant at p ≤ 0.025.

In the micronucleus test, it is preferable to base a positive result on the presence of both a positive trend as well as on at least one significantly elevated exposed group compared with the corresponding control group. In addition, historical control data are used to evaluate the biological significance of any observed response. Both statistical significance and biological significance are considered when arriving at a call. The presence of either a positive trend or a single significant exposed group generally results in an equivocal call. The absence of both a trend and any significant differences between exposed groups and the control group results in a negative call. Ultimately, the scientific staff determines the final call after considering the results of statistical analyses, reproducibility of any effects observed (in acute studies), and the magnitudes of those effects.

### D.3.2 Results

Micronuclei are biomarkers of chromosomal changes, either in chromosome number or structure (breaks). In the in vivo peripheral blood micronucleus test, TCPP exposure for 3 months via dosed feed did not result in an increase in micronucleated PCEs in male or female Sprague Dawley rats (Table D-3). However, the percentage of PCEs among total erythrocytes was increased in an exposure concentration-related manner in both sexes, suggesting a stimulation of erythropoiesis in the rats exposed to TCPP. In female B6C3F1/N mice, exposure to TCPP for 3 months via dosed feed did not result in an increase in micronucleated PCEs or NCEs (Table D-4). In male mice, the values for micronucleated red blood cells were within the laboratory historical control 95% confidence interval and the absolute increase in micronucleated NCEs and PCEs was quite small, amounting to an increase over control values of approximately 17% or 23%, respectively. Due to the questionable biological significance of the observed increase in micronucleated cells, the results in male mice were judged to be equivocal (Table D-4). In both male and female mice, the percentage of PCEs among total erythrocytes was increased in an exposure concentration-related manner, similar to what was observed in the rat samples, suggesting that exposure to TCPP also produced a stimulation of erythropoiesis in mice.

Table D-3 Frequency of Micronuclei in Peripheral Blood Erythrocytes of Male and Female Rats in the Three-month Feed Study of Tris(chloropropyl) Phosphate^a^

| Number of Rats with Erythrocytes Scored | Micronucleated PCEs/1,000 PCEs^b^ | P Value^c^ | Micronucleated NCEs/1,000 NCEs^b^ | P Value^c^ | PCEs (%)^b^ | P Value^c^
Male
Exposure Concentration (ppm)
0 | 5 | 0.388 ± 0.077 | | 0.031 ± 0.003 | | 0.869 ± 0.047
2,500 | 5 | 0.500 ± 0.096 | 0.3646 | 0.030 ± 0.008 | 1.0000 | 0.859 ± 0.078 | 1.0000
5,000 | 5 | 0.370 ± 0.075 | 0.4331 | 0.029 ± 0.004 | 1.0000 | 1.048 ± 0.056 | 0.0701
10,000 | 5 | 0.420 ± 0.085 | 0.4612 | 0.031 ± 0.006 | 1.0000 | 1.324 ± 0.057 | <0.001
Trend^d^ | | p = 0.5255 | | p = 0.5268 | | p < 0.001
Female
Exposure Concentration (ppm)
0 | 5 | 0.570 ± 0.051 | | 0.073 ± 0.018 | | 0.899 ± 0.069
2,500 | 5 | 0.676 ± 0.134 | 0.7823 | 0.085 ± 0.031 | 0.6955 | 1.040 ± 0.119 | 0.4322
5,000 | 5 | 0.380 ± 0.064 | 0.8558 | 0.050 ± 0.013 | 0.7793 | 1.129 ± 0.181 | 0.4080
10,000 | 5 | 0.460 ± 0.060 | 0.8851 | 0.057 ± 0.009 | 0.8131 | 1.030 ± 0.090 | 0.4362
20,000 | 5 | 0.310 ± 0.068 | 0.8970 | 0.033 ± 0.008 | 0.8297 | 1.522 ± 0.138 | 0.0049
Trend | | p = 0.9930 | | p = 0.9711 | | p = 0.0035

PCE = polychromatic erythrocyte; NCE = normochromatic erythrocyte.

^a^ Study was performed at Integrated Laboratory Systems, LLC.

^b^ Data are presented as mean ± standard error.

^c^ Pairwise comparisons with the vehicle control group performed using the Williams or Dunn test (p ≤ 0.025).

^d^ Exposure concentration-related trends evaluated by linear regression or the Jonckheere test (p ≤ 0.025).

Table D-4 Frequency of Micronuclei in Peripheral Blood Erythrocytes of Male and Female Mice in the Three-month Feed Study of Tris(chloropropyl)^a^

| Number of Rats with Erythrocytes Scored | Micronucleated PCEs/1,000 PCEs^b^ | P Value^c^ | Micronucleated NCEs/1,000 NCEs^b^ | P Value^c^ | PCEs (%)^b^ | P Value^c^
Male
Exposure Concentration (ppm)
0 | 5 | 2.630 ± 0.170 | | 1.462 ± 0.028 | | 1.360 ± 0.084
1,250 | 5 | 2.920 ± 0.200 | 0.3523 | 1.452 ± 0.012 | 1.0000 | 1.252 ± 0.029 | 1.0000
2,500 | 5 | 2.770 ± 0.137 | 0.4180 | 1.490 ± 0.011 | 1.0000 | 1.348 ± 0.036 | 1.0000
5,000 | 5 | 2.550 ± 0.328 | 0.4465 | 1.502 ± 0.030 | 0.8303 | 1.234 ± 0.044 | 1.0000
10,000 | 5 | 2.940 ± 0.183 | 0.2091 | 1.549 ± 0.022 | 0.1015 | 1.368 ± 0.050 | 0.9831
20,000 | 5 | 3.236 ± 0.217 | 0.0363 | 1.710 ± 0.028 | 0.0016 | 1.730 ± 0.052 | <0.001
Trend^d^ | | p = 0.0225 | | p < 0.001 | | p < 0.001
Female
Exposure Concentration (ppm)
0 | 5 | 2.860 ± 0.171 | | 1.133 ± 0.020 | | 1.120 ± 0.019
1,250 | 5 | 1.950 ± 0.110 | 0.9998 | 1.101 ± 0.041 | 0.9117 | 1.285 ± 0.087 | 0.2611
2,500 | 5 | 1.980 ± 0.107 | 1.0000 | 1.077 ± 0.009 | 0.9560 | 1.225 ± 0.084 | 0.3118
5,000 | 5 | 1.680 ± 0.133 | 1.0000 | 1.107 ± 0.024 | 0.9677 | 1.631 ± 0.106 | 0.0078
10,000 | 5 | 1.750 ± 0.177 | 1.0000 | 1.030 ± 0.041 | 0.9730 | 1.346 ± 0.107 | 0.0072
20,000 | 5 | 1.710 ± 0.189 | 1.0000 | 1.018 ± 0.018 | 0.9769 | 1.716 ± 0.089 | <0.001
Trend | | p = 0.9946 | | p = 0.9984 | | p < 0.001

PCE = polychromatic erythrocyte; NCE = normochromatic erythrocyte.

^a^ Study was performed at Integrated Laboratory Systems, LLC.

^b^ Data are presented as mean ± standard error.

^c^ Pairwise comparisons with the vehicle control group performed using the Williams or Dunn test (p ≤ 0.025).

^d^ Exposure concentration-related trends evaluated by linear regression or the Jonckheere test (p ≤ 0.025).