# Appendix C Sentinel Animal Program

## C.1 Methods

Rodents used in the National Toxicology Program are produced in optimally clean facilities to eliminate potential pathogens that might affect study results. The Sentinel Animal Program is part of the periodic monitoring of animal health that occurs during the toxicological evaluation of test compounds. Under this program, the disease state of the rodents is monitored via sera or feces from extra (sentinel) or exposed animals in the study rooms. The sentinel animals and the study animals are subject to identical environmental conditions. Furthermore, the sentinel animals come from the same production source and weanling groups as the animals used for the studies of test compounds.

For these toxicology and carcinogenesis studies, blood samples were collected from each sentinel animal and allowed to clot, and the serum was separated. Additionally, fecal samples were collected and tested for endoparasites and Helicobacter species. All samples were processed appropriately with serology and Helicobacter testing performed by IDEXX BioResearch (formerly Rodent Animal Diagnostic Laboratory [RADIL], University of Missouri), Columbia, MO, for determination of the presence of pathogens. Evaluation for endo- and ectoparasites was performed in-house by the testing laboratory.

The laboratory methods and agents for which testing was performed are tabulated below; the times at which samples were collected during the studies are also listed (Table C-1; Table C-2).

## C.2 Results

Rats: Positive for endoparasites, pinworms (Syphacia spp.). All other test results were negative.

Mice: All test results were negative.

Table C-1 Methods and Results for Sentinel Animal Testing in Male and Female Rats

Collection Time Points | Three-month Study | | | Two-year Study
Collection Time Points | Quarantine^a^ | Perinatal^b^ | Study Termination | Quarantine^a^ | Quarantine^c^ | Perinatal^b^ | 1 Month^d^ | 6 Months | 12 Months | 16 Months | 18 Months | Study Termination
Number Examined (Males/Females) | 0/10 | 0/10 | 5/5 | 0/10 | 0/1 | 0/10 | 5/5 | 5/5 | 5/5 | 1/0 | 5/5 | 5/5
Method/Test
Multiplex Fluorescent Immunoassay (MFI)
Kilham rat virus (KRV) | – | – | – | – | – | – | – | – | – | – | – | –
Mycoplasma pulmonis | – | – | – | – | – | – | – | – | – | – | – | –
Parvo NS-1 | – | – | – | NT | NT | NT | NT | NT | NT | NT | NT | NT
Pneumonia virus of mice (PVM) | – | – | – | – | – | – | – | – | – | – | – | –
Rat coronavirus/sialodacryoadenitis virus (RCV/SDA) | – | – | – | – | – | – | – | – | – | – | – | –
Rat minute virus (RMV) | – | – | – | – | – | – | – | – | – | – | – | –
Rat parvo virus (RPV) | – | – | – | – | – | – | – | – | – | – | – | –
Rat theilovirus (RTV) | – | – | – | – | – | – | – | – | – | – | – | –
Sendai | – | – | – | – | – | – | – | – | – | – | – | –
Theiler's murine encephalomyelitis virus (TMEV) | – | – | – | – | – | – | – | – | – | – | – | –
Toolan's H-1 | – | – | – | – | – | – | – | – | – | – | – | –
Immunofluorescence Assay (IFA)
Rat parvo virus (RPV) | NT | NT | NT | NT | NT | NT | NT | – | NT | NT | NT | NT
In-house Evaluation
Endoparasite evaluation (evaluation of cecal content) | NT | NT | NT | – | – | NT | – | NT | – | – | + | NT
Ectoparasite evaluation (evaluation of perianal surface) | NT | NT | NT | – | – | NT | – | NT | – | – | + | NT

– = negative; NT = not tested; + = positive.

^a^ Age-matched nonpregnant females.

^b^ Time-mated females that did not have a litter; 3.5 weeks after arrival.

^c^ Time-mated female—early euthanasia.

^d^ F_1_ animals tested 4 weeks after start of chronic phase.

Table C-2 Methods and Results for Sentinel Animal Testing in Male and Female Mice

Collection Time Points | Three-month Study | | Two-year Study
Collection Time Points | 1 Month^a^ | Study Termination | Quarantine | 1 Month | 6 Months | 12 Months | 18 Months | Study Termination
Number Examined (Males/Females) | 5/5 | 5/5 | 5/5 | 5/5 | 5/5 | 5/5 | 5/5 | 5/5
Method/Test
Multiplex Fluorescent Immunoassay (MFI)
Ectromelia virus | – | – | – | – | – | – | – | –
Epizootic diarrhea of infant mice (EDIM) | – | – | – | – | – | – | – | –
Lymphocytic choriomeningitis virus (LCMV) | – | – | – | – | – | – | – | –
Mycoplasma pulmonis | – | – | – | – | – | – | – | –
Mouse hepatitis virus (MHV) | – | – | – | – | – | – | – | –
Mouse norovirus (MNV) | – | – | – | – | – | – | – | –
Parvo NS-1 | – | – | – | – | – | – | – | –
Mouse parvovirus (MPV) | – | – | – | – | – | – | – | –
Minute virus of mice (MVM) | – | – | – | – | – | – | – | –
Pneumonia virus of mice (PVM) | – | – | – | – | – | – | – | –
Reovirus (REO3) | – | – | – | – | – | – | – | –
Sendai | – | – | – | – | – | – | – | –
Theiler's murine encephalomyelitis virus (TMEV) GDVII | – | – | – | – | – | – | – | –
Polymerase Chain Reaction (PCR)
Helicobacter species | NT | NT | NT | NT | NT | NT | – | NT
In-house Evaluation
Endoparasite evaluation (evaluation of cecal content) | NT | NT | – | – | NT | – | – | NT
Ectoparasite evaluation (evaluation of perianal surface) | NT | NT | – | – | NT | – | – | NT

− = negative; NT = not tested.

^a^ Four weeks after start of study.